# Peer Review

The Division of Translational Toxicology (DTT) at the National Institute of Environmental Health Sciences (NIEHS) conducted an external peer review of the draft NIEHS Report on the Toxicity Studies of Nicotine Bitartrate Dihydrate (CASRN 6019-06-3) Administered in Drinking Water to Sprague Dawley Rats and Swiss Mice by letter in February 2024 by the experts listed below. Reviewer selection and document review followed established DTT practices. The reviewers were charged to:

1. Peer review the draft NIEHS Report on the Toxicity Studies of Nicotine Bitartrate Dihydrate (CASRN 6019-06-3) Administered in Drinking Water to Sprague Dawley Rats and Swiss Mice.
2. Comment on DTT’s interpretations of the data.

DTT carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Alison Holloway, Ph.D.
  Associate Chair
  McMaster University
  Hamilton, Ontario, Canada
- Kamisha Johnson-Davis, Ph.D.
  Associate Professor
  University of Utah
  Salt Lake City, Utah, USA
- Wentai Luo, Ph.D.
  Senior Research Associate
  Portland State University
  Portland, Oregon, USA