# References

1 National Information Standards Organization (NISO). CRediT (Contributor Roles Taxonomy). Baltimore, MD: National Information Standards Organization; 2024. https://credit.niso.org/
2 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: (-)-Nicotine | 54-11-5 | DTXSID1020930. Washington, DC: U.S. Environmental Protection Agency; 2023. [Accessed: September 12, 2023]. https://comptox.epa.gov/dashboard/DTXSID1020930
3 Hukkanen J, Jacob P 3rd, Benowitz NL. Metabolism and disposition kinetics of nicotine. Pharmacol Rev. 2005; 57(1):79–115. 10.1124/pr.57.1.3 15734728
4 National Center for Biotechnology Information (NCBI). PubChem compound summary for CID 89594, nicotine. Bethesda, MD: National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2023. [Accessed: September 12, 2023]. https://pubchem.ncbi.nlm.nih.gov/compound/nicotine
5 O’Neil MJ. The Merck index: An encyclopedia of chemicals, drugs, and biologicals. 14th ed. Whitehouse Station, NJ: Merck and Co.; 2006.
6 Lewis RJ Sr. Sax’s dangerous properties of industrial materials. 11th ed. Hoboken, NJ: John Wiley & Sons; 2004. 10.1002/0471701343
7 National Institute for Occupational Safety and Health (NIOSH). Nicotine: Systemic agent. Cincinnati, OH: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2011. https://www.cdc.gov/niosh/ershdb/emergencyresponsecard_29750028.html
8 ChemSrc. Nicotine ditartrate dihydrate. 2023. [Accessed: September 12, 2023]. https://www.chemsrc.com/en/cas/6019-06-3_857016.html
9 National Center for Biotechnology Information (NCBI). PubChem compound summary for CID 2735102, nicotine bitartrate. Bethesda, MD: National Institutes of Health, National Library of Medicine, National Center for Biotechnology Information; 2023. [Accessed: September 12, 2023]. https://pubchem.ncbi.nlm.nih.gov/compound/Nicotine-Bitartrate
10 Connolly GN, Alpert HR, Wayne GF, Koh H. Trends in nicotine yield in smoke and its relationship with design characteristics among popular US cigarette brands, 1997-2005. Tob Control. 2007; 16(5):e5. 10.1136/tc.2006.019695 17897974
11 International Programme on Chemical Safety (IPCS). Nicotine. Geneva, Switzerland: World Health Organization, International Programme on Chemical Safety; 1991. https://www.inchem.org/documents/pims/chemical/nicotine.htm
12 Pacifici R, Draisci R. [Electronic cigarette: Available knowledge and public health actions]. Rome, Italy: Istituto Superiore di Sanità; 2013. Rapporti ISTISAN 13/42. https://www.iss.it/documents/20126/45616/13_42_web.pdf
13 U.S. Food and Drug Administration (FDA). Nicotine is why tobacco products are addictive. Silver Spring, MD: U.S. Department of Health and Human Services, Public Health Service, U.S. Food and Drug Administration; 2023. [Accessed: September 12, 2023]. https://www.fda.gov/tobacco-products/health-effects-tobacco-use/nicotine-why-tobacco-products-are-addictive
14 Wadgave U, Nagesh L. Nicotine replacement therapy: An overview. Int J Health Sci (Qassim). 2016; 10(3):425–435. 27610066
15 Center for Behavioral Health Statistics and Quality (CBHSQ). Results from the 2015 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: U.S. Department of Health and Human Services, Public Health Service, Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality; 2016. https://www.samhsa.gov/data/sites/default/files/NSDUH-DetTabs-2015/NSDUH-DetTabs-2015/NSDUH-DetTabs-2015.pdf
16 World Health Organization (WHO). WHO report on the global tobacco epidemic, 2017: Monitoring tobacco use and prevention policies. Geneva, Switzerland: World Health Organization; 2017. https://iris.who.int/handle/10665/255874
17 Benowitz NL, Hukkanen J, Jacob P 3rd. Nicotine chemistry, metabolism, kinetics and biomarkers. In: Henningfield JE, London ED, Pogun S, editors. Nicotine Psychopharmacology. Berlin, Germany: Springer; 2009. p. 29–60. 10.1007/978-3-540-69248-5_2
18 Sanner T, Grimsrud TK. Nicotine: Carcinogenicity and effects on response to cancer treatment – a review. Front Oncol. 2015; 5:196. 10.3389/fonc.2015.00196 26380225
19 Matta SG, Balfour DJ, Benowitz NL, Boyd RT, Buccafusco JJ, Caggiula AR, Craig CR, Collins AC, Damaj MI, Donny EC, et al. Guidelines on nicotine dose selection for in vivo research. Psychopharmacology (Berl). 2007; 190(3):269–319. 10.1007/s00213-006-0441-0 16896961
20 Florescu A, Ferrence R, Einarson T, Selby P, Soldin O, Koren G. Methods for quantification of exposure to cigarette smoking and environmental tobacco smoke: Focus on developmental toxicology. Ther Drug Monit. 2009; 31(1):14–30. 10.1097/FTD.0b013e3181957a3b 19125149
21 Göney G, Çok İ, Tamer U, Burgaz S, Şengezer T. Urinary cotinine levels of electronic cigarette (e-cigarette) users. Toxicol Mech Methods. 2016; 26(6):441–445. 10.3109/15376516.2016.1144127 27278718
22 U.S. Food and Drug Administration (FDA). Three-month extension of certain tobacco product compliance deadlines related to the final deeming rule; guidance for industry; availability. Fed Regist. 2017; 82(92):22338–22340. https://www.federalregister.gov/documents/2017/05/15/2017-09754/three-month-extension-of-certain-tobacco-product-compliance-deadlines-related-to-the-final-deeming.
23 U.S. Food and Drug Administration (FDA). FDA announces comprehensive regulatory plan to shift trajectory of tobacco-related disease, death. Silver Spring, MD: U.S. Department of Health and Human Services, Public Health Service, U.S. Food and Drug Administration; 2017. https://www.fda.gov/news-events/press-announcements/fda-announces-comprehensive-regulatory-plan-shift-trajectory-tobacco-related-disease-death
24 European Parliament and the Council of the European Union. Directive 2014/40/EU of the European Parliament and of the Council of 3 April 2014 on the approximation of the laws, regulations and administrative provisions of the member states concerning the manufacture, presentation and sale of tobacco and related products and repealing Directive 2001/37/EC. 2014. OJ L 127, 29.4.2014. https://eur-lex.europa.eu/eli/dir/2014/40/oj
25 Benowitz NL. Pharmacology of nicotine: Addiction, smoking-induced disease, and therapeutics. Annu Rev Pharmacol Toxicol. 2009; 49:57–71. 10.1146/annurev.pharmtox.48.113006.094742 18834313
26 Henstra C, Dekkers BGJ, Olgers TJ, ter Maaten JC, Touw DJ. Managing intoxications with nicotine-containing e-liquids. Expert Opin Drug Metab Toxicol. 2022; 18(2):115–121. 10.1080/17425255.2022.2058930 35345955
27 Ren M, Lotfipour S, Leslie F. Unique effects of nicotine across the lifespan. Pharmacol Biochem Behav. 2022; 214:173343. 10.1016/j.pbb.2022.173343 35122768
28 Slotkin TA. Developmental cholinotoxicants: Nicotine and chlorpyrifos. Environ Health Perspect. 1999; 107 Suppl 1:71–80. 10229709
29 Vivekanandarajah A, Waters KA, Machaalani R. Cigarette smoke exposure effects on the brainstem expression of nicotinic acetylcholine receptors (nAChRs), and on cardiac, respiratory and sleep physiologies. Respir Physiol Neurobiol. 2019; 259:1–15. 10.1016/j.resp.2018.07.007 30031221
30 Linker KE, Gad M, Tawadrous P, Cano M, Green KN, Wood MA, Leslie FM. Microglial activation increases cocaine self-administration following adolescent nicotine exposure. Nat Commun. 2020; 11(1):306. 10.1038/s41467-019-14173-3 31949158
31 Riebe M, Westphal K, Fortnagel P. Mutagenicity testing, in bacterial test systems, of some constituents of tobacco. Mutat Res. 1982; 101(1):39–43. 10.1016/0165-1218(82)90163-X 7043247
32 Haussmann HJ, Fariss MW. Comprehensive review of epidemiological and animal studies on the potential carcinogenic effects of nicotine per se. Crit Rev Toxicol. 2016; 46(8):701–734. 10.1080/10408444.2016.1182116 27278157
33 International Agency for Research on Cancer (IARC). Personal habits and indoor combustions. (IARC monographs on the evaluation of carcinogenic risks to humans; vol. 100E). Lyon, France: International Agency for Research on Cancer; 2012. https://publications.iarc.fr/122
34 Tang MS, Wu XR, Lee HW, Xia Y, Deng FM, Moreira AL, Chen LC, Huang WC, Lepor H. Electronic-cigarette smoke induces lung adenocarcinoma and bladder urothelial hyperplasia in mice. Proc Natl Acad Sci USA. 2019; 116(43):21727–21731. 10.1073/pnas.1911321116 31591243
35 Lunell E, Molander L, Ekberg K, Wahren J. Site of nicotine absorption from a vapour inhaler – comparison with cigarette smoking. Eur J Clin Pharmacol. 2000; 55(10):737–741. 10.1007/s002280050007 10663452
36 Benowitz NL, Jacob P 3rd. Daily intake of nicotine during cigarette smoking. Clin Pharmacol Ther. 1984; 35(4):499–504. 10.1038/clpt.1984.67 6705448
37 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
38 Armitage P. Statistical methods in medical research. Oxford, UK: Blackwell Scientific; 1971.
39 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
40 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
41 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
42 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
43 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
44 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957. 10.2307/2332898
45 National Toxicology Program (NTP). NIEHS Report 11: Chemical Effects in Biological Systems (CEBS) data repository. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2024. 10.22427/NIEHS-DATA-NIEHS-11
46 U.S. Public Health Service (USPHS). Smoking and health: Report of the advisory committee to the Surgeon General of the Public Health Service. Washington, DC: U.S. Department of Health, Education, and Welfare, Public Health Service; 1964. https://www.unav.edu/documents/16089811/16155256/Smoking+and+Health+the+Surgeon+General+Report+1964.pdf
47 U.S. Department of Health and Human Services (USDHHS). Chapter 1: Introduction, conclusions, and historical background relative to e-cigarettes. In: E-Cigarette Use Among Youth and Young Adults: A Report of the Surgeon General. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Center for Chronic Disease Prevention and Health Promotion, Office on Smoking and Health; 2016. https://www.ncbi.nlm.nih.gov/books/NBK538684/#ch1
48 Kapaya M, D’Angelo DV, Tong VT, England L, Ruffo N, Cox S, Warner L, Bombard J, Guthrie T, Lampkins A, et al. Use of electronic vapor products before, during, and after pregnancy among women with a recent live birth — Oklahoma and Texas, 2015. MMWR Morb Mortal Wkly Rep. 2019; 68(8):189–194. 10.15585/mmwr.mm6808a1 30817748
49 Sapru S, Vardhan M, Li Q, Guo Y, Li X, Saxena D. E-cigarettes use in the United States: Reasons for use, perceptions, and effects on health. BMC Public Health. 2020; 20(1):1518. 10.1186/s12889-020-09572-x 33032554
50 Slotkin TA, Lappi SE, McCook EC, Lorber BA, Seidler FJ. Loss of neonatal hypoxia tolerance after prenatal nicotine exposure: Implications for sudden infant death syndrome. Brain Res Bull. 1995; 38(1):69–75. 10.1016/0361-9230(95)00073-N 7552377
51 Slotkin TA, Orband-Miller L, Queen KL. Development of [3H]nicotine binding sites in brain regions of rats exposed to nicotine prenatally via maternal injections or infusions. J Pharmacol Exp Ther. 1987; 242(1):232–237. 3612529
52 Champagne FA, Francis DD, Mar A, Meaney MJ. Variations in maternal care in the rat as a mediating influence for the effects of environment on development. Physiol Behav. 2003; 79(3):359–371. 10.1016/S0031-9384(03)00149-5 12954431
53 Zhang W, Lin H, Zou M, Yuan Q, Huang Z, Pan X, Zhang W. Nicotine in inflammatory diseases: Anti-inflammatory and pro-inflammatory effects. Front Immunol. 2022; 13:826889. 10.3389/fimmu.2022.826889 35251010
54 Dussor GO, Leong AS, Gracia NB, Kilo S, Price TJ, Hargreaves KM, Flores CM. Potentiation of evoked calcitonin gene-related peptide release from oral mucosa: A potential basis for the pro-inflammatory effects of nicotine. Eur J Neurosci. 2003; 18(9):2515–2526. 10.1046/j.1460-9568.2003.02935.x 14622152
55 Galitovskiy V, Qian J, Chernyavsky AI, Marchenko S, Gindi V, Edwards RA, Grando SA. Cytokine-induced alterations of α7 nicotinic receptor in colonic CD4 T cells mediate dichotomous response to nicotine in murine models of Th1/Th17- versus Th2-mediated colitis. J Immunol. 2011; 187(5):2677–2687. 10.4049/jimmunol.1002711 21784975
56 Petersen DR, Norris KJ, Thompson JA. A comparative study of the disposition of nicotine and its metabolites in three inbred strains of mice. Drug Metab Dispos. 1984; 12(6):725–731. 6150822
57 Kyerematen GA, Taylor LH, deBethizy JD, Vesell ES. Pharmacokinetics of nicotine and 12 metabolites in the rat. Application of a new radiometric high performance liquid chromatography assay. Drug Metab Dispos. 1988; 16(1):125–129. 2894940
58 Benowitz NL, Porchet H, Jacob P 3rd. Pharmacokinetics, metabolism, and pharmacodynamics of nicotine. In: Wonnacott S, Russell MAH, Stolerman IP, editors. Nicotine Psychopharmacology: Molecular, Cellular, and Behavioural Aspects. Oxford, UK: Oxford University Press; 1990. p. 112–157. 10.1093/oso/9780192616142.003.0004
59 Armitage AK, Dollery CT, George CF, Houseman TH, Lewis PJ, Turner DM. Absorption and metabolism of nicotine from cigarettes. BMJ. 1975; 4(5992):313–316. 10.1136/bmj.4.5992.313 1192046
60 Russell MA, Jarvis M, Iyer R, Feyerabend C. Relation of nicotine yield of cigarettes to blood nicotine concentrations in smokers. BMJ. 1980; 280(6219):972–976. 10.1136/bmj.280.6219.972 7417765
61 Benowitz NL, Porchet H, Sheiner L, Jacob P 3rd. Nicotine absorption and cardiovascular effects with smokeless tobacco use: Comparison with cigarettes and nicotine gum. Clin Pharmacol Ther. 1988; 44(1):23–28. 10.1038/clpt.1988.107 3391001
62 Henningfield JE, Stapleton JM, Benowitz NL, Grayson RF, London ED. Higher levels of nicotine in arterial than in venous blood after cigarette smoking. Drug Alcohol Depend. 1993; 33(1):23–29. 10.1016/0376-8716(93)90030-T 8370337
63 Rose JE, Behm FM, Westman EC, Coleman RE. Arterial nicotine kinetics during cigarette smoking and intravenous nicotine administration: Implications for addiction. Drug Alcohol Depend. 1999; 56(2):99–107. 10.1016/S0376-8716(99)00025-3 10482401
64 Benowitz NL, Hall SM, Herning RI, Jacob P 3rd, Jones RT, Osman AL. Smokers of low-yield cigarettes do not consume less nicotine. N Engl J Med. 1983; 309(3):139–142. 10.1056/NEJM198307213090303 6866013
65 Geng Y, Savage SM, Johnson LJ, Seagrave J, Sopori ML. Effects of nicotine on the immune response. I. Chronic exposure to nicotine impairs antigen receptor-mediated signal transduction in lymphocytes. Toxicol Appl Pharmacol. 1995; 135(2):268–278. 10.1006/taap.1995.1233 8545837
66 Schneider NG, Olmstead RE, Franzon MA, Lunell E. The nicotine inhaler: Clinical pharmacokinetics and comparison with other nicotine treatments. Clin Pharmacokinet. 2001; 40(9):661–684. 10.2165/00003088-200140090-00003 11605715
67 Bloom AJ, Upadhyaya P, Kharasch ED. Strain-specific altered nicotine metabolism in 3,3′-diindolylmethane (DIM) exposed mice. Biopharm Drug Dispos. 2019; 40(5-6):188–194. 10.1002/bdd.2182 31016737
68 Curvall M, Kazemi Vala E, Englund G. Conjugation pathways in nicotine metabolism. In: Adlkofer F, Thurau K, editors. Effects of Nicotine on Biological Systems. Basel, Switzerland: Birkhäuser; 1991. p. 69–75. 10.1007/978-3-0348-7457-1_10
69 Byrd GD, Chang KM, Greene JM, deBethizy JD. Evidence for urinary excretion of glucuronide conjugates of nicotine, cotinine, and trans-3′-hydroxycotinine in smokers. Drug Metab Dispos. 1992; 20(2):192–197. 1352209
70 Benowitz NL, Jacob P 3rd. Metabolism of nicotine to cotinine studied by a dual stable isotope method. Clin Pharmacol Ther. 1994; 56(5):483–493. 10.1038/clpt.1994.169 7955812
71 Andersson G, Vala EK, Curvall M. The influence of cigarette consumption and smoking machine yields of tar and nicotine on the nicotine uptake and oral mucosal lesions in smokers. J Oral Pathol Med. 1997; 26(3):117–123. 10.1111/j.1600-0714.1997.tb00033.x 9083935
72 Hecht SS, Carmella SG, Murphy SE. Effects of watercress consumption on urinary metabolites of nicotine in smokers. Cancer Epidemiol Biomarkers Prev. 1999; 8(10):907–913. 10548320
73 ACD/Labs. NMR predictors. Toronto, Canada: Advanced Chemistry Development, Inc.; 2023. [Accessed: September 12, 2023]. https://www.acdlabs.com/products/spectrus-platform/nmr-predictors/
74 U.S. Pharmacopeia (USP). Nicotine. USP29-NF24 - 1522. Rockville, MD: United States Pharmacopeial Convention; 2006. http://www.pharmacopeia.cn/v29240/usp29nf24s0_m56620.html
75 U.S. Environmental Protection Agency (USEPA). Degradation of nicotine in chlorinated water: Pathways and kinetics. Washington, DC: U.S. Environmental Protection Agency; 2016. EPA Report No. EPA/600/R-16/073. https://nepis.epa.gov/Exe/ZyPURL.cgi?Dockey=P100TXXK.txt
76 National Research Council (NRC). Guide for the care and use of laboratory animals. 8th ed. Washington, DC: National Academies Press; 2011. 10.17226/12910