# Discussion

Evidence of the devastating health effects of smoking tobacco was summarized in the first report of the Surgeon General Advisory Committee on Smoking and Health in 1964, which reviewed the more than 7,000 articles already available at that time linking smoking to disease.^46^ In the nearly 60 years since the issuance of that report, many thousands of research papers have been published on the toxicity of tobacco smoke constituents, including formaldehyde, nitrosamines, carbon monoxide, and particulates. Less attention was given to understanding the role of nicotine, which accounts for more than 95% of tobacco alkaloids.^3^ Although recognized to possess potent pharmacological and addictive properties, nicotine is delivered in electronic cigarettes and is now a common ingredient in products designed to reduce or stop smoking, including gum and dermal patches. All these smoking-reduction aids are widely available over the counter.

In 2003, the modern electronic cigarette was developed, and this nicotine delivery system was introduced into the U.S. market in the mid-2000s.^47^ Electronic cigarette usage among women shortly before, during, or after pregnancy was estimated to be 7% in 2015.^48^ Among children, usage has increased rapidly during the last decade, as suggested in a survey indicating 4.9% of middle school and 20.7% of high school age students used electronic cigarettes in 2018.^49^

This pattern of increasing use of products containing nicotine, without the concurrent presence of other tobacco constituents, either combusted or chewed, prompted interest in further characterization of the toxicity and carcinogenicity of nicotine in rodent models.

Drinking water was chosen as the route of administration for these studies to mimic the episodic use of smoking replacement gums and electronic cigarettes and because absorption of nicotine across the oral mucosa is a primary route of delivery during use of these products.^35^ To select the test article, brief toxicokinetic studies of freebase (-)-nicotine and nicotine bitartrate dihydrate (NBD), a dihydrate salt complex, were performed first using a single gavage administration to male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. Toxicokinetic parameters, including the maximum plasma concentration (C_max_) and area under the plasma-concentration-versus-time curve (AUC), and conversion to the first metabolite cotinine were similar for both compounds. Because the NBD salt was more stable in aqueous solution, it was selected for these studies (Appendix B).

The palatability of NBD in dosing solutions was tested in Sprague Dawley rats and Swiss mice. In rats, the highest exposure concentration (100 mg/L) was discontinued after 24 hours because of a severe reduction in water consumption and reductions in body weight. Exposure to 50 mg/L induced significant reductions in body weights and water consumption in both sexes of rats by the end of the 2-week palatability study. Both the 50 and 100 mg/L exposure concentrations were considered unpalatable for rats. Therefore, the concentrations selected for the perinatal and 4-week study in rats were 0, 1.56, 3.12, 6.25, 12.5, and 25 mg/L. In mice, although some decreases in water consumption were observed, all exposure concentrations ≤100 mg/L were considered palatable and were selected for the 4-week study.

Rat dams receiving the two highest NBD concentrations (12.5 and 25 mg/L) in the perinatal and 4-week study consumed less feed and water, and the 25 mg/L dams gained significantly less weight during gestation and lactation than control dams. The mean number of pups per litter varied somewhat across the exposed groups but with no discernible exposure concentration-related pattern. Likewise, early pup mortality, which is common in Sprague Dawley rats that produce large litters, occurred in the control group as well as in exposed groups, again without a discernible pattern. Although body weight gains of pups were not markedly different from control pups, at the end of the lactation phase, an unusual wave of pup mortality was observed across exposed groups at concentrations ≥3.12 mg/L. In total, 42 pups died in the exposed groups, whereas no mortality was observed in the control group during the same period (postnatal day [PND] 19–24). At necropsy, some pups presented with gross lesions in the intestine, which correlated histopathologically with moderate diffuse intestinal inflammation. For this reason, NBD exposure was stopped for all exposed groups approximately 4 days before weaning. Thereafter, no additional pup mortality occurred, suggesting the deaths were exposure related. After weaning, pups’ NBD exposure was resumed at the concentrations given previously to their respective dams, resulting in no further mortality.

The possible reasons for this unexpected pup mortality remain speculative, but Slotkin and colleagues have extensively studied prenatal nicotine exposure and consequent postnatal deaths in rat pups exposed to periods of atmospheric hypoxia as a model to explore the strong statistical link between fetal exposure to cigarette smoke and sudden infant death syndrome.^28,50^ Noting that a peak of natural cholinergic stimulation during the second postnatal week is critical for the proper establishment of aspects of cerebro-cortical cytoarchitecture in Sprague Dawley rat pups, Slotkin’s group established that premature stimulation and resulting up-regulation and acquisition of cholinergic receptors^51^ by prenatal nicotine exposure leads to neurobehavioral abnormalities that appear immediately following birth and continue to express through adolescence.^28,50^ Slotkin and colleagues concluded that prenatal nicotine exposure results in an intolerance to postnatal hypoxia by interfering with heart rate and respiration control, causing a marked fall in pup heart and respiration rates leading to death instead of the normal increase in heart rate and respiration during hypoxic episodes. At the time of writing, this phenomenon has not been sufficiently studied to determine an expectation concerning dose response, and it presumably would also be sensitive to potential differences in maternal behaviors between litters that may limit oxygen availability to pups. Dams can nurse pups in a blanket posture, wherein the dam lays over the pups, or in an arched back or a passive posture, wherein the dam lays on her back or side, respectively.^52^ These different nursing positions may limit the oxygen available to pups. Therefore, an expectation of a traditional dose response in pup mortality, which was not seen in this study, may not be justified. Although the phenomenon described by Slotkin’s group may account in large part for the unexpected pattern of pup mortalities in this study, the observation that from PND 19 to PND 24, mortality did not occur at the lowest NBD exposure concentration group in the 4-week study—and that administration of this low exposure concentration during lactation (discussed below) resulted in all rat pups surviving to study termination in the 3-month study—suggests an additional role for nicotine during a vulnerable phase of postnatal maturation at the higher exposure concentrations.

At the end of the perinatal and 4-week study in rats, there were minor decreases in relative liver weights in males and relative adrenal weights in females at the top NBD exposure concentrations of 25 mg/L. Hematological findings of a significant increase in lymphocyte counts in females in all exposure groups except the highest (25 mg/L) were observed. Histopathological examination of the control and 25 mg/L groups revealed few significant lesions. Microscopic examination of the 25 mg/L and control groups (the only exposure groups evaluated) noted minimal inflammation of the intestine was increased in females but was not significant. Inflammation in the kidney was also noted in both sexes, and testicular lesions were noted in a few animals, but could not clearly be related to NBD exposure.

For the perinatal and 3-month study in rats, the design of the study and NBD drinking water concentrations were the same as in the perinatal and 4-week study, with the exception that all NBD-exposed groups received the lowest concentration of NBD during lactation. This approach was an attempt to prevent the late pup mortality seen in the lactational phase of the perinatal and 4-week study, and no pups died during the corresponding phase of the 3-month study. Patterns of reduced feed and water consumption by dams receiving the higher concentrations of NBD during gestation were similar to those in the earlier study and resulted again in reduced body weight at the top concentration (25 mg/L). There were no effects on litter size, sex ratio, pup survival, or body weight gains during lactation. Other than differences in body weights, there were no remarkable in-life effects of the NBD exposures on pups during the 3-month, postweaning study.

The pathology peer review of the perinatal and 3-month rat study did not identify any clear target organs associated with exposure to NBD. Various minimal to mild degenerative lesions in the testes were observed in a few animals in the 12.5 and 25 mg/L groups in the 3-month males and in the 25 mg/L group in the perinatal and 4-week study, and although rare at this young age in this strain of rat, they were not considered exposure related. Minimal inflammation was observed in a number of organs of rats from the perinatal and 4-week and 3-month studies, and while the incidence of this lesion was often greater in the NBD-exposed groups than in control rats, it rarely exhibited a clear exposure concentration response.

There is extensive and complex literature on nicotine and inflammation, recently reviewed by Zhang et al.^53^ The clearest evidence for proinflammatory effects of nicotine comes from studies of oral mucosal inflammation and periodontitis, a disease leading to frequent tooth loss in tobacco users. Dussor et al.^54^ in studies of buccal tissues isolated from Sprague Dawley rats, provided evidence that nicotine enhances the release of the proinflammatory factor calcitonin gene-related peptide through a neurogenic mechanism. Studies have shown an enhanced intestinal inflammatory response from nicotine in mouse models of Chron’s disease, but nicotine appears to be primarily anti-inflammatory in mouse models of ulcerative colitis.^55^ Nicotine has been extensively studied as a potential therapeutic agent to reduce inflammation in a wide variety of animal and human tissue models of immune or inflammation-related diseases, including inflammatory bowel disease, arthritis, multiple sclerosis, sepsis and endotoxemia, pancreatitis, and myocarditis. The interest in nicotine as an anti-inflammatory agent is because it activates cholinergic neural pathways that suppress inflammatory responses and because it acts directly on immune cells that can enhance apoptosis, inhibit inflammatory cytokine release, or modulate other inflammation processes.^53^

It is not clear whether the age dependencies and/or pharmacodynamics of these conflicting actions of nicotine on inflammatory processes could account for the observed patterns of minimal to mild inflammation in this study. Some of the more convincing evidence for proinflammatory responses was in the larynx, mandibular lymph nodes, large intestine, and kidney, the effect on which might be expected from direct oral exposures to nicotine. However, the generally minimal severity of these changes would suggest that they are presumably of nominal toxicological significance in animals once the cholinergic neural anti-inflammatory circuits become fully developed.

In the 4-week and 3-month studies in mice, no effects on survival, or biologically significant changes in body weight, feed consumption, or water consumption, were observed. There were no significant differences in organ weights. Histopathological evaluation of mice exposed to the highest concentration (100 mg/L) in the 4-week study noted a few instances of minimal or moderate inflammation in several organs, including the kidney in males and the Harderian gland in females; however, none were significant. In the 3-month study, there were incidences of increased minimal to mild inflammation in the kidney in male and female mice. Minimal inflammation in the jejunum, urinary bladder, and glandular stomach was also noted in female mice, with less evidence in these organs in exposed males. There were indications of increases in minimal focal inflammation in the Harderian gland and rectum in both sexes. Again, significance was lacking for all these measures, but when taken together with the sporadic occurrences of inflammatory lesions in the perinatal and 4-week and 3-month rat studies, they suggest a generalized minimal proinflammatory state associated with the NBD exposures. And, as with the findings from the rat studies, the toxicological significance of these minor inflammatory responses is uncertain.

When comparing mice to rat dams, mice were able to tolerate higher NBD drinking water concentrations. This observation was previously described by Matta et al.^19^ and may be due to differences in perception of taste and/or species differences in absorption and circulating half-life of nicotine (6–7 minutes in mice, approximately 1 hour in rats, and 2 hours in humans and nonhuman primates).^3,56-58^ In the current toxicokinetic studies, following oral administration of freebase (-)-nicotine or NBD, the time at which C_max_ occurred was typically between 0.5 and 1 hour; for cotinine (a major metabolite of nicotine), it was 4–4.67 hours for freebase (-)-nicotine and 4–5.33 hours for NBD, which suggests a slow conversion of nicotine to cotinine. No apparent sex-related effects on the toxicokinetic parameters or systemic exposure of cotinine were observed. Compared to nicotine, cotinine had a longer half-life, smaller apparent clearance of the central compartment and apparent volume of distribution for the central compartment, and greater systemic exposure (Appendix B).

In rats and mice, nicotine and cotinine concentrations in plasma and urine from the 3-month studies were largely dose proportional to the exposure concentrations. Nicotine intake was also estimated by normalizing nicotine and cotinine concentrations using water consumption data (data not shown). Overall, observations did not change when data were normalized to nicotine intake and did not shed light on the observed lack of dose-response for many of the minor pathology findings discussed above. The nicotine plasma concentrations from rats (Figure C-1) and mice (Figure C-3) ranged from below to somewhat above reported human plasma concentrations (15–80 ng/mL) following smoking one cigarette (approximately 2 mg nicotine/cigarette).^35,59-63^ Cotinine concentrations in rat (Figure C-2) and mouse (Figure C-4) plasma also ranged below and above reported human plasma concentrations. Blood cotinine concentrations were reported to range between 250 and 350 ng/mL for regular smokers and up to 900 ng/mL for heavy smokers.^36,64-66^

Nicotine metabolism in humans and other species is well studied, and various metabolites are reported.^3^ In this study, in addition to nicotine and cotinine concentrations in plasma and urine samples, a qualitative assessment was performed to determine the presence and concentration estimates of some of the main nicotine and cotinine metabolites (trans-3’-hydroxycotinine, cotinine-N-oxide, cotinine N-β-D-glucuronide, norcotinine, nornicotine, trans-3’-hydroxycotinine-O-B-D-glucuronide, nicotine-1’-oxide, and nicotine N-β-D-glucuronide) that are reported in the literature. Metabolites were present in varying concentrations in both plasma and urine of rats and mice (Table C-3). Metabolite concentrations in mouse plasma were higher than in rat plasma, which may be due to mice having significantly higher in vivo CYP2A activity relative to rats.^67^ Cotinine N-β-D-glucuronide concentrations were the highest in rat and mouse plasma within all the metabolites analyzed. Although trans-3’-hydroxy cotinine was not detected in rat plasma, it was present at relatively low concentrations in mouse plasma across all exposure groups. Trans-3’-hydroxycotinine and its glucuronide conjugate are reported as the main urinary nicotine metabolites detected in smokers.^3,68-72^ These metabolites were reported as minor in rats and with no measurable glucuronidation activity in rat or mouse liver microsomes.^3^ Trans-3’-hydroxy cotinine O-β-D-glucuronide, nicotine N-β-D-glucuronide, and cotinine N-β-D-glucuronide in urine were not reportable in the current analyses, largely due to interfering peaks observed in the chromatography in rat and mouse samples.

In conclusion, studies were performed to examine the palatability, metabolism, toxicokinetic, and toxic responses to NBD administered in drinking water to rats beginning on gestation day (GD) 6 and extending through 4 weeks or 3 months postweaning and to adult mice similarly exposed to NBD in drinking water for 4 weeks or 3 months. Mice tolerated higher NBD drinking water concentrations relative to rats. Rates of nicotine clearance were higher in both rodent species than in humans. Other than reductions in feed and water consumption and resulting lower body weight gains at the higher exposure levels, there were no clinical findings considered to be of clear toxicological significance for the NBD exposures in rats or mice. However, there was a high rate of mortality of rat pups receiving NBD at concentrations ≥3.12 mg/L during the late-lactation phase of the perinatal and 4-week study that was unexpected and may be related to inhibition of normal cholinergic neural development by prenatal nicotine exposures. No mortality was observed in the control group and in the exposed group at 1.56 mg/L during the same period. This finding prompted a change in the design of the perinatal and 3-month study in rats to provide all groups of exposed lactating dams the same lowest NBD exposure concentration (1.56 mg/L), which effectively prevented pup mortalities during this apparently vulnerable developmental period. The only other findings of note were observations of generally minimal inflammation across many organ systems in rats and mice. These were often of low incidence, not related to exposure concentration, and were not considered to be of clear toxicological significance.