# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NIEHS-DATA-NIEHS-11.^45^

## Two-week Palatability Study in Rats and Mice

All rats and mice completed the 2-week palatability study of nicotine bitartrate dihydrate (NBD) except for rats exposed to 100 mg nicotine/L (mg/L), which were euthanized after 24 hours in compliance with animal welfare guidelines because of severe reductions in water consumption (78% in males and 88% in females) and mean body weight (7% in males and 12% in females) (Appendix D). All NBD dose formulations refer to the freebase (-)-nicotine concentrations. No exposure-related gross or microscopic lesions occurred in exposed rats or mice. Final mean body weight was significantly decreased in male and female rats exposed to 50 mg/L, and final mean water consumption was significantly decreased in male and female rats exposed to 50 mg/L and female rats exposed to 12.5 and 25 mg/L. Water consumption was significantly decreased by mice at most exposure concentrations, although the study still complied with animal welfare guidelines. In conclusion, exposure to NBD in drinking water at concentrations up to 25 mg/L (rats) or 100 mg/L (mice) for 2 weeks was well tolerated, and the solutions were considered palatable.

## Rats

### Perinatal and Four-week Dose Range-finding Study (Perinatal Phase)

Exposure to NBD had no effects on the percentages of dams with litters, gestation length, or litter size (Table 4). On postnatal day (PND) 1, litter sizes for exposed groups were 74%–97% of the control group; however, these decreases were not exposure-related (Table 4).

Table 4 Summary of the Disposition of Rats during Perinatal Exposure in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

| 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
F_0_ Reproductive Performance
Time-mated Females (GD 6)^b^ | 5 | 5 | 5 | 5 | 5 | 5
Females Pregnant (%)^b^ | 5 (100) | 5 (100) | 5 (100) | 5 (100) | 5 (100) | 5 (100)
Females Not Pregnant (%)^b^ | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Dams Not Delivering with Evidence of Pregnancy (%)^b^ | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Dams with Litters on LD 0 (%)^b^ | 5 (100) | 5 (100) | 5 (100) | 5 (100) | 5 (100) | 5 (100)
Gestation Length (Days)^b,c^ | 22 ± 0 | 21.8 ± 0.45 | 22 ± 0 | 22 ± 0 | 22 ± 0 | 21.8 ± 0.45
Mean Litter Size and Survival
Litter Size on PND 1^b,d,e,f^ | 17.2 (5) | 12.8 (5) | 16.6 (5) | 14.2 (5) | 15.4 (5) | 15.6 (5)
Mean Number of Male Pups per Litter on PND 4^b,d,e^ | 9 (5) | 5.6 (5) | 10 (5) | 6.2 (5) | 9.2 (5) | 7.4 (5)
Mean Number of Female Pups per Litter on PND 4^b,d,e^ | 7.6 (5) | 6.8 (5) | 5.6 (5) | 7.8 (5) | 6 (5) | 6.6 (5)
Survival per Litter^e,g^
Total dead: PND 1–18 | 6 (4) | 2 (2) | 5 (3) | 2 (2) | 1 (1) | 8 (3)
Total dead: PND 19–24^h^ | 0 (5) | 0 (5) | 22** (4) | 2 (2) | 13** (5) | 5* (2)
Weaned Males/Females^b^ | 44/36 | 28/34 | 34/22 | 29/38 | 37/25 | 34/31

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ No statistical analyses were performed on these endpoints.

^c^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as a mean ± standard deviation.

^d^ Data are presented as a mean (number of dams).

^e^ Each exposed group was compared to the vehicle control group with Fisher’s exact test.

^f^ Pups were sexed on PND 4.

^g^ Total dead in exposure group (number of litters).

^h^ Due to high pup mortality during lactation, nicotine bitartrate dihydrate exposure was interrupted, and all animals were given tap water instead of dosed water from ~4 days before weaning until the start of the 4-week study.

All F_0_ dams survived until study termination (Table 5), and no clinical observations recorded during the study were considered related to exposure. Mean body weights of all groups of F_0_ dams were similar at the beginning of gestation (gestation day [GD] 5); however, mean body weight gain of the 25 mg/L group was lower than that of the control group (Table 5; Figure 2). By the end of gestation (GD 21), mean body weight of the 25 mg/L group was 90% of that of the control group. Throughout lactation, mean body weights of 25 mg/L dams remained ≤90% of that of the control group, reaching 86% by lactation day (LD) 21 (Figure 2; Appendix D).

Table 5 Summary of Survival, Mean Body Weights, and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Parameter^b,c^ | 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
Gestation Body Weight
Gestation Day
5^d^ | 314.0 ± 15.6 (5) | 316.0 ± 10.8 (5) | 310.0 ± 21.8 (5) | 305.0 ± 5.0 (5) | 302.0 ± 9.1 (5) | 320.0 ± 11.2 (5)
21 | 475.0 ± 23.5 (5) | 479.0 ± 36.0 (5) | 469.0 ± 32.7 (5) | 446.0 ± 8.2 (5) | 448.0 ± 5.7 (5) | 427.0 ± 25.1* (5)
Gestation Weight Change
Gestation Day Interval
5–21 | 161.0 ± 14.3 (5) | 163.0 ± 25.6 (5) | 159.0 ± 15.2 (5) | 141.0 ± 12.4 (5) | 146.0 ± 6.5 (5) | 107.0 ± 18.2** (5)
Lactation Body Weight
Lactation Day
1 | 327.0 ± 16.0 (5) | 326.0 ± 15.6 (5) | 322.0 ± 14.8 (5) | 306.0 ± 11.9 (5) | 302.0 ± 4.5 (5) | 292.0 ± 22.2** (5)
21 | 359.0 ± 13.4 (5) | 360.0 ± 15.4 (5) | 346.0 ± 19.8 (5) | 339.0 ± 17.8 (5) | 324.0 ± 15.6* (5) | 307.0 ± 18.9** (5)
Lactation Weight Change
Lactation Day Interval
1–21 | 32.0 ± 14.0 (5) | 34.0 ± 18.2 (5) | 24.0 ± 9.6 (5) | 33.0 ± 11.5 (5) | 22.0 ± 16.8 (5) | 15.0 ± 3.5 (5)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation (number of dams). Body weight data are presented in grams.

^d^ Body weights were evaluated 1 day prior to study start and initiation of exposure on gestation day 6.

Figure 2

Gestation and Lactation Growth Curves for F_0_ Female Rats in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) gestation and (B) lactation.

Before initiation of exposure (GD 5), mean water consumption (mL/animal/day) by the 25 mg/L group was approximately 83% of that of the control group (Table 6). Beginning on GD 6, water consumption by the 25 mg/L group dropped dramatically and was <60% of that of the control group for most of the remaining exposure period, ending with a mean water consumption value approximately 37% of that of the control group on GD 21 (Appendix D). Starting on GD 8, mean water consumption by the 12.5 mg/L group was <70% of that of the control group for most of the remaining exposure period, whereas mean water consumption by the 1.56, 3.12, and 6.25 mg/L groups was <90% of that of the control group for most of the remaining time points.

Table 6 Summary of Water and Nicotine Bitartrate Dihydrate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Four-week Dose Range-finding Drinking Water Study^a^

Parameter | 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
Gestation Day (mL/animal/day)^b,c^
5^d^ | 46.0 ± 8.4 (5) | 35.6 ± 6.1 (5) | 43.2 ± 5.8 (5) | 46.4 ± 6.1 (5) | 40.0 ± 8.5 (5) | 38.0 ± 4.2 (5)
21 | 51.2 ± 3.3 (5) | 35.6 ± 6.7** (5) | 36.4 ± 7.0** (5) | 40.4 ± 7.0 (5) | 31.6 ± 7.4** (5) | 18.8 ± 6.1** (5)
Chemical Intake (mg/kg/day)^e,f^
GD 5–21 | 0 | 0.2 | 0.4 | 0.8 | 1.4 | 2.0
Lactation Day (mL/animal/day)^b,c^
1 | 40.0 ± 6.5 (5) | 39.2 ± 2.7 (5) | 41.2 ± 5.8 (5) | 42.4 ± 8.5 (5) | 33.6 ± 6.7 (5) | 29.2 ± 5.9* (5)
21 | 153.2 ± 23.1 (5) | 148.0 ± 22.5 (5) | 146.8 ± 22.1 (5) | 140.4 ± 22.0 (5) | 123.2 ± 21.7 (5) | 84.4 ± 15.8** (5)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine only.

^b^ Data are presented as mean ± standard deviation (number of dams).

^c^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^d^ Water consumption was evaluated 1 day prior to study start and initiation of exposure on gestation day 6.

^e^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^f^ No statistical analysis performed on the chemical intake data.

On LD 1, mean water consumption by the 25 mg/L group was approximately 73% of that of the control group; at all subsequent measurements, it was 53%–61% of that of the control group (Table 6; Appendix D). From LD 4 to LD 21, mean water consumption by the 12.5 mg/L group was ≤80% of that of the control group. Water consumption by the other exposed groups was <90% of that of the control group during most of lactation but within 10% of the control group by LD 21.

Mean feed consumption by the 25 mg/L group was <90% of that of the control group from GD 6 to GD 12, after which consumption decreased significantly, ending at approximately 51% of that of the control group on GD 21 (Table 7; Appendix D). Mean feed consumption by the 12.5 mg/L group was consistently <90% of that of the control group, beginning at GD 8, and <90% that of the other exposed groups at some time points.

Table 7 Summary of Feed Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Parameter^b,c^ | 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
Gestation Day (g/animal/day)
5^d^ | 24.0 ± 2.2 (5) | 25.0 ± 3.5 (5) | 26.0 ± 4.2 (5) | 26.0 ± 2.2 (5) | 25.0 ± 6.1 (5) | 27.0 ± 5.7 (5)
21 | 37.0 ± 2.7 (5) | 26.0 ± 8.2* (5) | 27.0 ± 4.5 (5) | 27.0 ± 4.5 (5) | 27.0 ± 4.5 (5) | 19.0 ± 8.9** (5)
Lactation Day (g/animal/day)
1 | 25.0 ± 0.0 (5) | 30.0 ± 7.1 (5) | 30.0 ± 0.0 (5) | 24.0 ± 4.2 (5) | 23.0 ± 4.5 (5) | 22.0 ± 2.7 (5)
21 | 100.0 ± 10.0 (5) | 95.0 ± 7.9 (5) | 90.0 ± 10.0 (5) | 92.0 ± 7.6 (5) | 78.0 ± 15.2** (5) | 70.0 ± 10.0** (5)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Data are presented as mean ± standard deviation (number of dams).

^c^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^d^ Feed consumption was evaluated 1 day prior to study start and initiation of exposure on gestation day 6.

Similar to the pattern observed in gestation, mean feed consumption throughout lactation was lower for all exposed groups relative to the control group, with only a couple of exceptions early in lactation (Table 7). By the end of lactation (LD 21), mean feed consumption was 70% of that of the control group for the 25 mg/L group and 78% for the 12.5 mg/L group. The remaining exposed groups had mean feed consumption values within 10% of the control group at LD 21.

There were no significant changes in preweaning pup mean body weights; however, both male and female pups exposed to 25 mg/L had lower body weights at all time points and were <90% of the control group by PND 14 for females and PND 21 for males. Mean body weights of male and female pups in the 25 mg/L groups were approximately 88%–93% and 86%–92%, respectively, of that of the control groups (Table 8).

Table 8 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Nicotine Bitartrate Dihydrate^a^

Postnatal Day^b,c^ | 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
Male
4 | 9.2 ± 0.8 (45/5) | 10.4 ± 1.1 (28/5) | 9.0 ± 0.9 (50/5) | 9.5 ± 1.2 (31/5) | 8.6 ± 0.4 (46/5) | 8.5 ± 0.9 (37/5)
7 | 12.4 ± 1.8 (44/5) | 14.8 ± 1.1 (28/5) | 12.3 ± 1.3 (50/5) | 12.9 ± 2.0 (31/5) | 11.5 ± 0.7 (46/5) | 11.5 ± 1.2 (37/5)
14 | 22.1 ± 2.7 (44/5) | 26.4 ± 2.7 (28/5) | 22.0 ± 1.9 (50/5) | 22.9 ± 4.6 (31/5) | 21.0 ± 1.3 (46/5) | 20.2 ± 2.4 (37/5)
21 | 31.6 ± 4.9 (44/5) | 39.8 ± 5.9 (28/5) | 29.8 ± 3.6 (40/5) | 33.1 ± 7.6 (30/5) | 29.4 ± 2.6 (44/5) | 27.7 ± 4.2 (37/5)
Female
4 | 8.8 ± 0.8 (38/5) | 10.1 ± 0.7 (34/5) | 8.5 ± 1.1 (28/5) | 9.0 ± 1.1 (39/5) | 8.3 ± 0.6 (30/5) | 8.1 ± 1.2 (33/5)
7 | 11.9 ± 1.5 (37/5) | 13.9 ± 1.3 (34/5) | 11.4 ± 1.8 (28/5) | 12.1 ± 2.0 (39/5) | 11.0 ± 0.6 (29/5) | 10.8 ± 1.6 (33/5)
14 | 21.5 ± 2.6 (36/5) | 25.4 ± 2.6 (34/5) | 20.8 ± 2.9 (28/5) | 21.8 ± 4.1 (38/5) | 20.0 ± 1.7 (29/5) | 19.1 ± 3.1 (33/5)
21 | 30.5 ± 5.0 (36/5) | 38.1 ± 5.5 (34/5) | 29.5 ± 3.9 (24/5) | 31.1 ± 6.8 (38/5) | 28.2 ± 3.4 (28/5) | 26.3 ± 5.2 (33/5)

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant differences were noted at p ≤ 0.05.

^c^ Data are presented as the mean of litter means ± standard deviation (number of pups/number of litters). Body weight data are presented in grams.

During lactation (PND 19–24), pup mortality in the 3.12, 12.5, and 25 mg/L groups was significantly increased compared to the control group. In total, 42 pups died across all exposed groups, whereas no mortality was observed in the control group during the same period. Because of the observed mortality, exposure was suspended in all groups at approximately 4 days before weaning; thereafter, no additional pup mortality was observed, suggesting that the higher incidence of mortality was exposure related. At necropsy, pups from the exposed groups who died between PNDs 19 and 24 presented gross lesions in the intestine, which correlated histopathologically with moderately diffuse intestinal inflammation (Appendix D).

### Perinatal and Four-week Dose Range-finding Study (Postweaning Phase)

After exposure was suspended (LD 22–25, depending on parturition date of the litter), pups were weaned on LD 26–29 and were not exposed again until 4 days after weaning. After resumption of exposure, no additional mortalities occurred until study termination (Table 9).

Table 9 Summary of Survival, Mean Body Weights, and Body Weight Gains of Male and Female Rats in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate, with Two-week Recovery Period^a^

Study Day^b,c,d^ | 0 mg/L | | 1.56 mg/L | | 3.12 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L
Study Day^b,c,d^ | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n
Male
Exposure Period
1 | 89.4 ± 9.2 | 20 | 97.2 ± 12.2 | 10 | 82.5 ± 11.1 | 10 | 89.1 ± 19.5 | 10 | 76.1 ± 10.2* | 10 | 74.7 ± 10.3** | 20
7^e^ | 152.9 ± 11.6 | 20 | 168.3 ± 18.1 | 10 | 144.3 ± 14.2 | 10 | 151.4 ± 24.0 | 10 | 131.3 ± 16.4 | 10 | 126.7 ± 14.9 | 20
14^e^ | 202.2 ± 13.8 | 20 | 221.7 ± 19.3 | 10 | 194.9 ± 16.1 | 10 | 198.2 ± 25.9 | 10 | 177.5 ± 20.7 | 10 | 169.6 ± 18.6 | 20
21 | 251.9 ± 15.2 | 20 | 276.6 ± 17.8* | 10 | 246.0 ± 15.8 | 10 | 254.2 ± 30.9 | 10 | 227.2 ± 22.6* | 10 | 215.4 ± 21.5** | 20
28^e,f^ | 297.1 ± 18.4 | 20 | 333.5 ± 23.0 | 10 | 293.8 ± 20.2 | 10 | 289.3 ± 30.5 | 10 | 278.6 ± 27.8 | 10 | 248.8 ± 23.2 | 20
Recovery Period^g^
35 | 331.8 ± 13.0 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 301.8 ± 27.0** | 10
42^e,f^ | 364.4 ± 14.4 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 337.6 ± 27.6 | 10
Weight Change
1–21 | 162.5 ± 11.7 | 20 | 179.4 ± 6.7** | 10 | 163.5 ± 8.4 | 10 | 165.1 ± 18.8 | 10 | 151.1 ± 13.2 | 10 | 140.7 ± 12.3** | 20
Female
Exposure Period
1 | 81.8 ± 7.7 | 20 | 87.6 ± 9.2 | 10 | 74.8 ± 12.1 | 10 | 81.3 ± 15.6 | 10 | 68.4 ± 9.5** | 10 | 67.8 ± 10.1** | 20
7^e^ | 128.5 ± 9.6 | 20 | 139.9 ± 8.3 | 10 | 123.4 ± 12.7 | 10 | 127.9 ± 17.3 | 10 | 112.3 ± 10.1 | 10 | 107.9 ± 12.3 | 20
14^e^ | 151.6 ± 10.8 | 20 | 168.2 ± 9.3 | 10 | 150.2 ± 13.0 | 10 | 154.4 ± 17.4 | 10 | 138.8 ± 10.3 | 10 | 132.2 ± 11.0 | 20
21 | 177.1 ± 13.3 | 20 | 197.2 ± 11.0** | 10 | 175.8 ± 14.2 | 10 | 176.5 ± 17.9 | 10 | 160.1 ± 9.3** | 10 | 153.7 ± 13.3** | 20
28^e,f^ | 194.2 ± 16.3 | 20 | 222.3 ± 16.6 | 10 | 202.5 ± 12.0 | 10 | 202.2 ± 18.1 | 10 | 178.2 ± 12.6 | 10 | 173.7 ± 13.7 | 20
Recovery Period^g^
35 | 219.7 ± 15.2 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 200.6 ± 14.8* | 10
42^e,f^ | 237.9 ± 14.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 218.1 ± 16.8 | 10
Weight Change
1–21 | 95.3 ± 7.6 | 20 | 109.6 ± 3.4** | 10 | 101.0 ± 6.0 | 10 | 95.2 ± 7.1 | 10 | 91.7 ± 4.7 | 10 | 86.0 ± 6.2** | 20

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation. Body weight data are presented in grams.

^d^ Study day 1 is the day animals were placed on study after weaning. Study day 1 corresponds to postnatal day 30 of the last litter born.

^e^ No statistical analysis performed on this endpoint.

^f^ On study day 28, measurements were taken after 10 rats from each exposure group were moved to metabolic cages for 16 hours. On study day 42 (recovery period), measurements were taken after 10 rats each from the control group and 25 mg/L group were moved to metabolic cages for 16 hours.

^g^ Data for the recovery period were collected for only 10 rats each from the control group and 25 mg/L group.

Mean body weights of the 1.56 mg/L male and female groups were significantly higher than the control group at study day 21, with significantly higher weight gain from study day 1 to 21 in males and females. At higher concentrations, the mean body weights of the 12.5 and 25 mg/L male and female groups were <90% of those of the control groups on study day 1 (Table 9; Figure 3). The 12.5 mg/L groups were within 10% of the control groups by study day 14 for female rats and study day 21 for male rats. Mean body weights of the 25 mg/L male and female groups remained <90% of those of their respective control groups for the entire exposure period; however, mean body weights of the 25 mg/L male and female recovery groups were within 10% of those of the control groups by the end of the recovery period (Table 9). No clinical observations observed during the study were considered exposure related (Appendix D).

Figure 3

Growth Curves for Male and Female Rats in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) males and (B) females.

In male rats, mean water consumption (mL/animal/day) by the ≥6.25 mg/L groups was <90% of that of the control group for the entire 4 weeks of exposure, with consumption by the 25 mg/L group <70% of that of the control group (Table 10). During the 2-week recovery period (with no exposure), mean water consumption by the 25 mg/L group was similar to that of the control group (Table 10).

Table 10 Summary of Water and Nicotine Bitartrate Dihydrate Consumption by Male and Female Rats in the Perinatal and Four-week Dose Range-finding Drinking Water Study, with Two-week Recovery Period^a^

Study Day | 0 mg/L | | 1.56 mg/L | | 3.12 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L
Study Day | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
Water (mL/animal/day)^b,c^
Exposure Period
1 | 20.8 ± 2.1 | 20 | 21.7 ± 2.8 | 10 | 22.3 ± 3.9 | 10 | 18.4 ± 2.5 | 10 | 14.0 ± 0.8** | 10 | 12.3 ± 1.7** | 20
21 | 39.0 ± 4.6 | 20 | 38.9 ± 2.3 | 10 | 37.5 ± 2.9 | 10 | 32.3 ± 1.6** | 10 | 31.7 ± 3.2** | 10 | 26.5 ± 2.1** | 20
28^d^ | 42.6 ± 1.2 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 45.2 ± 10.1 | 10
Recovery Period^e^
35 | 43.2 ± 5.2 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 39.9 ± 2.5 | 10
42^d,f^ | 37.8 ± 16.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 38.4 ± 17.5 | 10
Chemical Intake (mg/kg/day)^f,g,h^
1–21 | 0 | 20 | 0.3 | 10 | 0.6 | 10 | 1.0 | 10 | 2.0 | 10 | 3.5 | 20
Female
Water (mL/animal/day)^b,c^
Exposure Period
1 | 19.9 ± 1.4 | 20 | 21.6 ± 2.3 | 10 | 22.7 ± 5.2 | 10 | 19.2 ± 1.6 | 10 | 13.8 ± 1.4** | 10 | 11.3 ± 1.8** | 20
21 | 28.7 ± 3.7 | 20 | 31.2 ± 1.3 | 10 | 28.6 ± 3.0 | 10 | 26.3 ± 1.1 | 10 | 20.7 ± 2.8** | 10 | 15.6 ± 3.1** | 20
28^d^ | 35.3 ± 0.6 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 31.1 ± 1.7** | 10
Recovery Period^e^
35 | 34.9 ± 2.2 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 27.3 ± 1.1** | 10
42^d,f^ | 38.8 ± 16.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 32.4 ± 14.1 | 10
Chemical Intake (mg/kg/day)^f,g,h^
1–21 | 0 | 20 | 0.3 | 10 | 0.6 | 10 | 1.1 | 10 | 2.0 | 10 | 3.2 | 20

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation.

^d^ On study day 28, measurements were not taken for the 10 rats from each exposure group moved to metabolic cages. On study day 42 (recovery period), measurements were taken after 10 rats each from the control and high exposure groups were moved to metabolic cages for 16 hours.

^e^ Data for the recovery period were collected for only 10 rats each from the control group and 25 mg/L group.

^f^ No statistical analysis performed on the chemical intake data.

^g^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^h^ Milligrams of freebase (-)-nicotine consumed/kg body weight/day.

In female rats, mean water consumption by the 25 mg/L group was ≤61% of that of the control group throughout exposure (Table 10) and did not return to control group values during recovery, reaching 84% at the end of recovery week 2 (study day 42) (Table 10). Mean water consumption by the 12.5 mg/L group was approximately 70% of that of the control group throughout exposure (Table 10). For the other exposed groups, mean water consumption was generally within 10% to 15% of that of the control group.

In male rats, mean feed consumption by the 25 mg/L group was <90% of that of the control group for the entire 4 weeks of exposure; during the 2-week recovery period (with no exposure), mean feed consumption was similar to that of the control group (Table 11). Mean feed consumption by the 3.12, 6.25, and 12.5 mg/L groups was <90% of that of the control group on study days 1 (12.5 mg/L group only), 7, and 21 (Appendix D). In female rats, mean feed consumption by the 25 mg/L group was <90% of that of the control group throughout most of the exposure period and returned to within 10% of the control group during the recovery period (Table 11). Mean feed consumption by the 12.5 mg/L group was approximately 76% of that of the control group on study day 1 but was within 10% of the control group for the remainder of the study.

Table 11 Summary of Feed Consumption by Male and Female Rats in the Perinatal and Four-week Drinking Dose Range-finding Water Study of Nicotine Bitartrate Dihydrate, with Two-week Recovery Period^a^

Study Day^b,c^ | 0 mg/L | | 1.56 mg/L | | 3.12 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L
Study Day^b,c^ | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
Feed (g/animal/day)
Exposure Period
1 | 13.8 ± 1.8 | 20 | 14.5 ± 1.7 | 10 | 12.4 ± 0.6 | 10 | 12.8 ± 2.4 | 10 | 10.3 ± 1.6** | 10 | 9.6 ± 1.4** | 20
21 | 26.1 ± 3.8 | 20 | 27.9 ± 1.9 | 10 | 23.3 ± 2.0 | 10 | 22.6 ± 0.8 | 10 | 23.2 ± 2.5 | 10 | 21.7 ± 2.2* | 20
28^d^ | 25.2 ± 2.4 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 25.6 ± 0.8 | 10
Recovery Period^e^
35 | 26.3 ± 0.6 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 25.1 ± 2.5 | 10
Female
Feed (g/animal/day)
Exposure Period
1 | 12.2 ± 0.8 | 20 | 12.9 ± 0.5 | 10 | 11.8 ± 1.5 | 10 | 12.0 ± 0.7 | 10 | 9.3 ± 1.2** | 10 | 9.1 ± 1.4** | 20
21 | 16.1 ± 2.0 | 20 | 18.7 ± 2.5 | 10 | 16.6 ± 2.1 | 10 | 17.3 ± 1.0 | 10 | 15.1 ± 1.3 | 10 | 12.5 ± 2.9* | 20
28^d^ | 17.3 ± 0.3 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 18.5 ± 0.8* | 10
Recovery Period^e^
35 | 18.2 ± 2.5 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 16.8 ± 0.9 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Data are presented as mean ± standard deviation.

^c^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^d^ On study day 28, measurements were not taken for the 10 rats from each exposure group moved to metabolic cages.

^e^ Data for the recovery period were collected for only 10 rats each from the control group and 25 mg/L group.

At the end of the 4-week study, there were no exposure-related changes in the clinical chemistry parameters for either sex. There were no hematological findings in male rats, but the white blood cell counts and lymphocyte counts were significantly increased at all exposure concentrations with the exception of the 25 mg/L female exposed group (Appendix D). Causes of lymphocyte count increases in rats include excitation (physiological leukocytosis) or chronic inflammation. There was increased incidence of minimal intestinal inflammation in histopathologically examined female rats in the 25 mg/L group (Appendix D); animals used for clinical chemistry analysis, which exhibited significantly increased lymphocyte counts, were not evaluated histopathologically. While the significant increase in the lymphocyte counts may have been due to mild inflammation or antigenic stimulation, biological variability could not be ruled out. No changes in the white blood cell count or lymphocyte count were observed in the 2-week recovery animals, which included only control rats and rats in the 25 mg/L group. There were no marked changes in urinalysis measures that were considered biologically significant (Appendix D).

In male rats, mean absolute liver weight for the 25 mg/L group was 72% of that of the control group, and relative liver weight was also significantly decreased (Table 12). Mean absolute urinary bladder and prostate weights (combined) were significantly decreased in the 25 mg/L group compared to those of the control group. There were no histopathological correlations with these organ weight changes (Table 13; Appendix D). Male rats in the 25 mg/L group had several other organs with mean absolute weights <90% of those of the control group, including the thymus and mediastinal lymph nodes (combined), heart, spleen, kidneys, and adrenal glands; however, relative organ weights were similar to those of the control group. The lower absolute weights probably reflect differences in terminal body weights. In male rats, all mean organ weights of the 25 mg/L group were within 10% of the control group after postexposure recovery, except for the absolute spleen, thymus, and mediastinal lymph node weights (Appendix D).

Table 12 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Rats in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a,b,c^

| 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Terminal Body Wt. (g) | 303.40 ± 20.35 | 333.50 ± 22.99* | 293.80 ± 20.18 | 289.30 ± 30.51 | 278.60 ± 27.78 | 246.90 ± 22.61**
Liver
Absolute (g) | 11.896 ± 1.251 | 13.265 ± 1.187* | 11.912 ± 0.810 | 11.662 ± 1.436 | 10.787 ± 0.816 | 8.565 ± 1.286**
Relative (mg/g)^d^ | 39.256 ± 3.816 | 39.750 ± 1.610 | 40.571 ± 1.653 | 40.791 ± 6.955 | 38.840 ± 1.999 | 34.570 ± 2.740*
Urinary Bladder and Prostate (Combined)
Absolute (g) | 0.392 ± 0.052 | 0.429 ± 0.077 | 0.430 ± 0.153 | 0.396 ± 0.076 | 0.316 ± 0.055 | 0.261 ± 0.057**
Relative (mg/g) | 1.289 ± 0.133 | 1.288 ± 0.218 | 1.449 ± 0.437 | 1.389 ± 0.318 | 1.134 ± 0.175 | 1.051 ± 0.191
Thymus and Mediastinal Lymph Nodes (Combined)
Absolute (g) | 0.888 ± 0.147 | 0.906 ± 0.125 | 0.871 ± 0.104 | 0.760 ± 0.127 | 0.822± 0.074 | 0.653 ± 0.065**
Relative (mg/g) | 2.943 ± 0.552 | 2.731 ± 0.439 | 2.991 ± 0.513 | 2.651 ± 0.506 | 2.969 ± 0.326 | 2.666 ± 0.398
Heart
Absolute (g) | 1.147 ± 0.064 | 1.259 ± 0.159 | 1.122 ± 0.083 | 1.074 ± 0.110 | 1.044 ± 0.075 | 0.935 ± 0.072**
Relative (mg/g) | 3.785 ± 0.159 | 3.769 ± 0.324 | 3.820 ± 0.145 | 3.744 ± 0.512 | 3.762 ± 0.213 | 3.798 ± 0.203
Spleen
Absolute (g) | 0.632 ± 0.067 | 0.689 ± 0.077 | 0.627 ± 0.082 | 0.575 ± 0.054 | 0.634 ± 0.088 | 0.548 ± 0.133
Relative (mg/g) | 2.091 ± 0.267 | 2.072 ± 0.241 | 2.131 ± 0.209 | 2.001 ± 0.241 | 2.291 ± 0.366 | 2.215 ± 0.477
Kidneys
Absolute (g) | 2.267 ± 0.121 | 2.551 ± 0.236** | 2.219 ± 0.165 | 2.320 ± 0.179 | 2.220 ± 0.206 | 1.961 ± 0.227**
Relative (mg/g) | 7.498 ± 0.568 | 7.649 ± 0.449 | 7.558 ± 0.336 | 8.097 ± 1.033 | 7.983 ± 0.394 | 7.937 ± 0.510
Adrenal Glands
Absolute (g) | 0.062 ± 0.019 | 0.061 ± 0.014 | 0.051 ± 0.010 | 0.058 ± 0.006 | 0.057 ± 0.013 | 0.045 ± 0.009**
Relative (mg/g) | 0.207 ± 0.075 | 0.181 ± 0.036 | 0.174 ± 0.030 | 0.202 ± 0.026 | 0.204 ± 0.045 | 0.182 ± 0.033
Female
Terminal Body Wt. (g) | 190.50 ± 18.67 | 222.30 ± 16.56** | 202.50 ± 12.30 | 202.20 ± 18.08 | 178.20 ± 12.62 | 177.00 ± 12.16
Liver
Absolute (g) | 7.329 ± 1.655 | 9.104 ± 0.945** | 8.459 ± 0.551 | 8.086 ± 0.638 | 6.927 ± 0.905 | 7.032 ± 0.994
Relative (mg/g) | 38.152 ± 5.646 | 41.121 ± 4.829 | 41.804 ± 2.045 | 40.029 ± 0.836 | 38.818 ± 3.814 | 39.578 ± 3.382
Heart
Absolute (g) | 0.786 ± 0.055 | 0.887 ± 0.063** | 0.821 ± 0.078 | 0.799 ± 0.073 | 0.755 ± 0.089 | 0.702 ± 0.059**
Relative (mg/g) | 4.141 ± 0.194 | 4.001 ± 0.303 | 4.051 ± 0.272 | 3.963 ± 0.350 | 4.228 ± 0.329 | 3.963 ± 0.179
Spleen
Absolute (g) | 0.434 ± 0.038 | 0.546 ± 0.177* | 0.448 ± 0.046 | 0.504 ± 0.130 | 0.449 ± 0.076 | 0.429 ± 0.074
Relative (mg/g) | 2.287 ± 0.217 | 2.453 ± 0.522 | 2.208 ± 0.131 | 2.483 ± 0.545 | 2.517 ± 0.377 | 2.435 ± 0.444
Kidney
Absolute (g) | 1.489 ± 0.115 | 1.711 ± 0.109** | 1.583 ± 0.081 | 1.593 ± 0.129 | 1.498 ± 0.115 | 1.454 ± 0.115
Relative (mg/g) | 7.836 ± 0.401 | 7.715 ± 0.486 | 7.826 ± 0.300 | 7.894 ± 0.436 | 8.407 ± 0.372** | 8.214 ± 0.279
Adrenal Glands
Absolute (g)^e^ | 0.061 ± 0.009 | 0.065 ± 0.015 | 0.060 ± 0.007 | 0.061 ± 0.007 | 0.054 ± 0.004 | 0.046 ± 0.010**
Relative (mg/g)^e^ | 0.320 ± 0.028 | 0.292 ± 0.066 | 0.294 ± 0.026 | 0.301 ± 0.029 | 0.304 ± 0.030 | 0.258 ± 0.054**
Uterus
Absolute (g) | 0.480 ± 0.129 | 0.472 ± 0.105 | 0.528 ± 0.167 | 0.440 ± 0.185 | 0.461 ± 0.172 | 0.387 ± 0.150
Relative (mg/g) | 2.548 ± 0.802 | 2.130 ± 0.467 | 2.606 ± 0.801 | 2.192 ± 0.913 | 2.603 ± 1.043 | 2.181 ± 0.810
Ovaries
Absolute (g) | 0.122 ± 0.022 | 0.142 ± 0.023 | 0.135 ± 0.014 | 0.145 ± 0.019 | 0.137 ± 0.026 | 0.125 ± 0.023
Relative (mg/g) | 0.642 ± 0.088 | 0.637 ± 0.087 | 0.666 ± 0.053 | 0.717 ± 0.086 | 0.775 ± 0.166* | 0.706 ± 0.128

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard deviation.

^b^ Statistical analysis performed with the Dunnett (pairwise) test.

^c^ Concentrations in drinking water refer to freebase (-)-nicotine.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight per g body weight.

^e^ One animal weighed in the 25 mg/L group had agenesis of the adrenal gland.

Table 13 Incidences of Select Nonneoplastic Lesions in Male and Female Rats in the Perinatal and Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

| 0 mg/L | 25 mg/L
Male
Intestines (All Sites)^b^ | 10 | 10
Inflammation, minimal^c,d^ | 2 | 2
Kidney | 10 | 10
Inflammation, peritubular, minimal | 0 | 2
Inflammation, focal, minimal | 2 | 3
Testes | 10 | 10
Degeneration, tubules, minimal | 0 | 1
Degeneration, tubules, multinucleated cells with necrosis, mild | 0 | 2
Female
Intestines (All Sites) | 10 | 10
Inflammation, minimal | 2 | 5
Kidney | 10 | 9
Inflammation, peritubular, minimal | 0 | 1
Inflammation, focal, minimal | 1 | 3

^a^ Concentration in drinking water refers to freebase (-)-nicotine.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ The exposed group was compared to the vehicle control group using Fisher’s exact (pairwise) test. No statistically significant findings were noted at p ≤ 0.05.

In female rats, mean absolute and relative adrenal gland weights were significantly decreased in the 25 mg/L group compared to the control group (Table 12). One animal was recorded as having agenesis of the adrenal gland (Appendix D). Mean absolute weights of the heart and uterus of the 25 mg/L group were <90% of those of the control group; however, the relative organ weights indicate this change was probably due to differences in terminal body weights. Several groups had absolute organ weights that were ≥110% of those of the control group; however, relative organ weights were similar to those of the control group, indicating that the differences were likely due to body weight differences. These organs included the spleen, liver, and kidney of the 1.56 mg/L group; the liver of the 3.12 mg/L group; and the liver and ovaries of the 6.25 mg/L group. In female rats, mean absolute spleen, liver, and uterus weights of the 25 mg/L group were ≤90% of those of the control group after postexposure recovery; however, given the relative weights, these changes were most likely due to body weight differences (Appendix D).

#### Histopathology

This section describes the incidences of select nonneoplastic lesions in the intestines (all sites), kidney, and testes. The incidences were not statistically significant. The control and 25 mg/L groups were the only groups examined microscopically.

Intestines (all sites): Minimal inflammation of the intestine (all sites combined) was present in the 25 mg/L and control male and female rats (Table 13).

Kidney: Minimal focal or peritubular inflammation was present in the kidneys of 25 mg/L male and female rats and minimal focal inflammation was observed in the control groups (Table 13).

Testes: Degenerative lesions in the testes were recorded in three male rats in the 25 mg/L group; none were recorded in the control group (Table 13). These lesions included minimal tubule degeneration and mild tubule degeneration of multinucleated cells with necrosis, which are considered rare for Sprague Dawley rats of this age.

### Exposure Concentration Selection Rationale for the Perinatal and Three-month Study

The perinatal and 4-week study provided information for the selection of exposure concentrations for the perinatal and 3-month study in rats. In the perinatal and 4-week study, pup mortality was observed in all exposed groups during lactation, except at the lowest exposure concentration of 1.56 mg/L. Therefore, the exposure concentrations selected for the perinatal and 3-month study in rats were 0, 1.56, 3.12, 6.25, 12.5, and 25 mg/L (concentration of freebase (-)-nicotine from NBD) in drinking water, except during lactation, when all exposed groups, dams and pups, received 1.56 mg/L.

### Perinatal and Three-month Study (Perinatal Phase)

All F_0_ dams survived until study termination (Appendix D), and no clinical observations recorded during the study were considered related to exposure. All animals were pregnant, and there was no effect of NBD exposure on dams with litters, gestation length, or sex ratio (Table 14).

Table 14 Summary of the Disposition of Rats during Perinatal Exposure in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

| 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
F_0_ Reproductive Performance^b^
Time-mated Females (GD 6) | 8 | 8 | 8 | 8 | 8 | 8
Females Pregnant (%) | 8 (100) | 8 (100) | 8 (100) | 8 (100) | 8 (100) | 8 (100)
Females Not Pregnant (%) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Dams Not Delivering with Evidence of Pregnancy (%) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Dams with Litters on LD 0 (%) | 8 (100) | 8 (100) | 8 (100) | 8 (100) | 8 (100) | 8 (100)
Gestation Length (Days)^c^ | 22 ± 0 | 22 ± 0 | 22 ± 0 | 22 ± 0 | 22 ± 0 | 22 ± 0
Mean Litter Size and Survival^b^
Mean Number of Male Pups per Litter on PND 1^d,e,f^ | 6.6 ± 2.0 (8) | 7.8 ± 1.8 (8) | 8.5 ± 2.4 (8) | 8.5 ± 2.4 (8) | 8.1 ± 2.7 (8) | 7.3 ± 1.8 (8)
Mean Number of Female Pups per Litter on PND 1^d,e,f^ | 6.6 ± 2.5 (8) | 7.8 ± 1.7 (8) | 7.1 ± 1.6 (8) | 7.6 ± 2.3 (8) | 7.9 ± 1.6 (8) | 6.9 ± 1.6 (8)
Weaned Males/Females^f^ | 51/53 | 62/62 | 67/56 | 66/58 | 59/60 | 58/53

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ No statistical analyses were performed on these endpoints.

^c^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as a mean ± standard deviation.

^d^ Litters were not standardized in this study.

^e^ Data are presented as mean ± standard deviation (number of dams).

^f^ During lactation, all exposed animals received the same dose of 1.56 mg/L because of the high pup mortality during lactation in the previous 4-week study.

Throughout gestation and lactation, mean body weights of exposed groups of F_0_ dams were within 10% of that of the control group (Table 15; Figure 4; Appendix D). The largest difference was observed at the end of gestation, when the mean body weight of the 25 mg/L dams was approximately 8% lower than that of the control group.

Table 15 Summary of Survival, Mean Body Weights, and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Parameter^b,c^ | 0 mg/L | 1.56 mg/L | 3.12 mg/L^d^ | 6.25 mg/L^d^ | 12.5 mg/L^d^ | 25 mg/L^d^
Gestation Body Weight
Gestation Day
5^e^ | 316.9 ± 16.7 (8) | 323.1 ± 12.2 (8) | 324.4 ± 20.3 (8) | 320.0 ± 16.9 (8) | 320.0 ± 16.5 (8) | 325.6 ± 9.4 (8)
21 | 458.8 ± 11.3 (8) | 475.6 ± 12.4 (8) | 479.4 ± 33.5 (8) | 476.9 ± 23.7 (8) | 449.4 ± 17.2 (8) | 422.5 ± 13.9** (8)
Gestation Weight Change
Gestation Day Interval
5–21 | 141.9 ± 11.3 (8) | 152.5 ± 14.1 (8) | 155.0 ± 16.5 (8) | 156.9 ± 8.8 (8) | 129.4 ± 11.2 (8) | 96.9 ± 13.6** (8)
Lactation Body Weight
Lactation Day
1 | 327.5 ± 17.1 (8) | 335.0 ± 14.6 (8) | 333.8 ± 21.3 (8) | 326.3 ± 20.0 (8) | 305.6 ± 13.7* (8) | 302.5 ± 9.3* (8)
28 | 314.4 ± 21.1 (8) | 314.4 ± 12.4 (8) | 316.3 ± 19.8 (8) | 310.0 ± 15.8 (8) | 306.9 ± 13.9 (8) | 308.8 ± 17.5 (8)
Lactation Weight Change
Lactation Day Interval
1–28 | −13.1 ± 13.3 (8) | −20.6 ± 9.8 (8) | −17.5 ± 17.3 (8) | −16.3 ± 13.8 (8) | 1.3 ± 3.5 (8) | 6.3 ± 13.3* (8)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation (number of dams). Body weight data are presented in grams.

^d^ During lactation, all exposed animals received the same drinking water concentration of 1.56 mg/L because of the high pup mortality during lactation in the previous 4-week study.

^e^ Body weights were evaluated 1 day prior to study start and initiation of exposure on gestation day 6.

Figure 4

Gestation and Lactation Growth Curves for F_0_ Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) gestation and (B) lactation.

Before exposure (GD 5), mean water consumption (mL/animal/day) by dams in the 25 mg/L group was approximately 118% of that of the control group (Table 16). On GD 6, however, it fell to 47% of that of the control group (Appendix D). Throughout gestation, mean water consumption by the 25 mg/L group remained less than that of the control group and was approximately 58% of that of the control group on GD 21 (Table 16). The 6.25 and 12.5 mg/L groups also consumed less water on average than the control group (significantly reduced at 12.5 mg/L on GD 21). During lactation, when exposure was limited to 1.56 mg/L, mean water consumption by all exposed groups was similar to that of the control group (Table 16; Appendix D).

Table 16 Summary of Water and Nicotine Bitartrate Dihydrate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study^a^

Parameter | 0 mg/L | 1.56 mg/L | 3.12 mg/L^b^ | 6.25 mg/L^b^ | 12.5 mg/L^b^ | 25 mg/L^b^
Gestation Day (mL/animal/day)^c,d^
5^e^ | 37.1 ± 5.1 (8) | 42.5 ± 7.1 (8) | 45.3 ± 7.6 (8) | 40.6 ± 6.2 (8) | 40.1 ± 4.5 (8) | 43.8 ± 7.2 (8)
21 | 42.0 ± 8.3 (8) | 41.8 ± 7.4 (8) | 39.8 ± 7.7 (8) | 38.8 ± 10.3 (8) | 24.8 ± 5.2** (8) | 24.5 ± 5.6** (8)
Chemical Intake (mg/kg/day)^f,g^
GD 5–21 | 0 | 0.2 | 0.4 | 0.7 | 1 | 1.4
Lactation Day(mL/animal/day)^c,d^
1 | 45.5 ± 5.6 (8) | 42.3 ± 13.4 (8) | 49.8 ± 7.4 (8) | 42.5 ± 8.6 (8) | 54.0 ± 6.7 (8) | 55.8 ± 8.2 (8)
28 | 282.5 ± 33.1 (8) | 303.5 ± 50.5 (8) | 309.8 ± 44.6 (8) | 290.5 ± 25.6 (8) | 297.3 ± 51.8 (8) | 282.8 ± 63.6 (8)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01.

GD = gestation day.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ During lactation, all exposed animals received the same exposure concentration of 1.56 mg/L because of the high pup mortality during lactation in the previous 4-week study.

^c^ Data are presented as mean ± standard deviation (number of dams).

^d^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^e^ Water consumption was evaluated 1 day prior to study start and initiation of exposure on gestation day 6.

^f^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

Mean feed consumption by the 25 mg/L group was slightly higher (approximately 117%) than that of the control group prior to exposure on GD 5 (Table 17). On GD 6, however, it fell to 82% of that of the control group and remained <90% throughout gestation (Appendix D). Mean feed consumption by the 12.5 mg/L group was also less than that of the control group throughout gestation and was approximately 80% of that of the control group on GD 21, though not significantly different. During lactation, when exposure was limited to 1.56 mg/L, mean feed consumption by all exposed groups was similar to that of the control group (Table 17).

Table 17 Summary of Feed Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Parameter^b,c^ | 0 mg/L | 1.56 mg/L | 3.12 mg/L^d^ | 6.25 mg/L^d^ | 12.5 mg/L^d^ | 25 mg/L^d^
Gestation Day (g/animal/day)
5^e^ | 21.9 ± 3.7 (8) | 23.1 ± 5.3 (8) | 24.4 ± 4.2 (8) | 20.6 ± 5.0 (8) | 22.5 ± 2.7 (8) | 25.6 ± 3.2 (8)
21 | 28.1 ± 4.6 (8) | 31.3 ± 5.8 (8) | 28.8 ± 5.8 (8) | 26.9 ± 3.7 (8) | 22.5 ± 2.7 (8) | 23.8 ± 4.4 (8)
Lactation Day (g/animal/day)
1 | 27.5 ± 4.6 (8) | 27.5 ± 9.3 (8) | 28.1 ± 7.5 (8) | 25.6 ± 7.3 (8) | 30.6 ± 5.0 (8) | 33.8 ± 5.2 (8)
28 | 148.1 ± 10.3 (8) | 166.3 ± 16.9 (8) | 161.3 ± 10.3 (8) | 160.0 ± 14.9 (8) | 164.4 ± 14.0 (8) | 155.0 ± 16.5 (8)

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Data are presented as mean ± standard deviation (number of dams).

^c^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant findings were noted at p ≤ 0.05.

^d^ During lactation, all exposed animals received the same exposure concentration of 1.56 mg/L because of the high pup mortality during lactation in the previous 4-week study.

^e^ Feed consumption was evaluated 1 day prior to study start and initiation of exposure on gestation day 6.

For F_1_ male and female rats, pup viability, number of live pups per litter, live litter size, and sex ratio were similar to the control groups during lactation (Table 14, Table 18).

Table 18 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Nicotine Bitartrate Dihydrate^a^

Postnatal Day^b,c^ | 0 mg/L | 1.56 mg/L | 3.12 mg/L^d^ | 6.25 mg/L^d^ | 12.5 mg/L^d^ | 25 mg/L^d^
Male
1 | 7.5 ± 0.5 (53/8) | 7.1 ± 0.4 (62/8) | 7.3 ± 0.5 (68/8) | 7.4 ± 0.4 (68/8) | 7.0 ± 0.3 (65/8) | 6.9 ± 0.5 (58/8)
4 | 10.4 ± 1.0 (52/8) | 9.3 ± 0.7 (62/8) | 9.6 ± 1.0 (67/8) | 9.5 ± 1.0 (68/8) | 9.2 ± 0.8 (63/8) | 9.6 ± 1.0 (58/8)
7 | 14.1 ± 1.9 (51/8) | 12.7 ± 1.1 (62/8) | 12.9 ± 1.5 (67/8) | 12.5 ± 1.8 (67/8) | 12.6 ± 1.2 (62/8) | 13.4 ± 1.5 (58/8)
14 | 25.1 ± 3.2 (51/8) | 22.1 ± 1.9 (62/8) | 22.5 ± 2.6 (67/8) | 22.2 ± 3.7 (66/8) | 23.9 ± 5.2 (60/8) | 23.4 ± 2.7 (58/8)
21 | 38.9 ± 6.4 (51/8) | 33.1 ± 3.5 (62/8) | 33.9 ± 4.7 (67/8) | 33.3 ± 6.3 (66/8) | 34.2 ± 3.8 (59/8) | 35.9 ± 5.0 (58/8)
28 | 67.1 ± 9.7 (51/8) | 59.2 ± 5.4 (62/8) | 59.9 ± 7.7 (67/8) | 58.6 ± 8.6 (66/8) | 60.3 ± 4.9 (59/8) | 63.2 ± 7.7 (58/8)
Female
1 | 7.1 ± 0.5 (53/8) | 6.7 ± 0.3 (62/8) | 6.8 ± 0.4 (57/8) | 6.8 ± 0.5 (61/8) | 6.6 ± 0.3 (63/8) | 6.3 ± 0.5 (55/8)
4 | 9.8 ± 1.1 (53/8) | 8.9 ± 0.6 (62/8) | 9.1 ± 0.9 (57/8) | 8.9 ± 1.2 (59/8) | 8.7 ± 0.7 (62/8) | 9.1 ± 0.9 (54/8)
7 | 13.5 ± 1.9 (53/8) | 12.2 ± 1.3 (62/8) | 12.3 ± 1.5 (57/8) | 12.4 ± 1.8 (58/8) | 12.1 ± 1.0 (61/8) | 12.7 ± 1.5 (54/8)
14 | 23.6 ± 3.1 (53/8) | 21.4 ± 2.3 (62/8) | 21.6 ± 2.6 (56/8) | 21.5 ± 3.7 (58/8) | 21.6 ± 2.3 (60/8) | 22.5 ± 2.9 (53/8)
21 | 37.6 ± 6.6 (53/8) | 31.6 ± 4.0 (62/8) | 32.8 ± 5.4 (56/8) | 33.1 ± 6.9 (58/8) | 33.4 ± 3.4 (60/8) | 35.5 ± 5.2 (53/8)
28 | 63.7 ± 9.5 (53/8) | 55.8 ± 6.1 (62/8) | 57.4 ± 8.0 (56/8) | 56.9 ± 9.0 (58/8) | 57.9 ± 4.4 (60/8) | 61.1 ± 7.8 (53/8)

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Data are presented as the mean of litter means ± standard deviation (number of pups/number of litters). Body weight data are presented in grams.

^d^ During lactation, all exposed dams received the same exposure concentration of 1.56 mg/L because of the high pup mortality during lactation in the previous 4-week study.

On PND 1, mean body weights of male and female pups in the 12.5 and 25 mg/L groups were 93% and 91% (males) and 93% and 89% (females) of control animals, respectively. During lactation, male and female pups in the ≤12.5 mg/L groups had mean body weights that were 85%–92% of the control groups from PND 4 through PND 28 (Table 18; Figure 5; Appendix D). Mean body weights of male and female pups in the 25 mg/L group were similar to those of the control groups on PND 28.

Figure 5

Preweaning Growth Curves for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) males and (B) females.

### Perinatal and Three-month Study (Postweaning Phase)

All male and female rats survived to study termination, and no clinical observations recorded during the study were considered exposure related (Appendix D).

Mean body weights of all exposed groups of male and female rats were 83%–87% of those of the control groups in week 1 (Table 19; Figure 6). By week 4, nearly all mean body weights of all exposed groups of both sexes were within 10% of the control groups (Appendix D). At week 12, mean body weights of male rats in the 25 mg/L group remained significantly decreased at 90% of the control group, and all other exposed groups were within 5% of the control group. Mean body weights of exposed female rats were also lower at 12 weeks but within 7% of that of the control group.

Table 19 Summary of Survival, Mean Body Weights, and Body Weight Gains of Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Week^b,c^ | 0 mg/L | | 1.56 mg/L | | 3.12 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L
Week^b,c^ | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n
Male
Body Weight
1^d^ | 92.1 ± 6.6 | 10 | 77.3 ± 5.6** | 10 | 76.1 ± 9.0** | 10 | 79.5 ± 6.6** | 10 | 79.0 ± 6.8** | 10 | 79.6 ± 5.9** | 10
12^e^ | 480.7 ± 28.5 | 10 | 484.3 ± 26.3 | 10 | 475.2 ± 35.5 | 10 | 469.0 ± 28.2 | 10 | 455.3 ± 27.4 | 10 | 431.3 ± 32.0** | 10
Body Weight Change
1–12 | 388.6 ± 22.7 | 10 | 407.0 ± 27.3 | 10 | 399.1 ± 36.4 | 10 | 389.5 ± 25.7 | 10 | 376.3 ± 29.6 | 10 | 351.7 ± 32.2* | 10
Female
Body Weight
1^d^ | 85.2 ± 6.1 | 10 | 70.4 ± 3.5** | 10 | 70.5 ± 9.2** | 10 | 74.3 ± 8.7** | 10 | 74.3 ± 3.9** | 10 | 74.5 ± 5.4** | 10
12^e^ | 292.6 ± 16.7 | 10 | 289.6 ± 18.4 | 10 | 279.8 ± 19.8 | 10 | 276.3 ± 18.0 | 10 | 280.7 ± 18.6 | 10 | 271.7 ± 18.3 | 10
Body Weight Change
1–12 | 207.4 ± 18.6 | 10 | 219.2 ± 19.6 | 10 | 209.3 ± 18.2 | 10 | 202.0 ± 17.4 | 10 | 206.4 ± 18.5 | 10 | 197.2 ± 20.7 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation. Body weight data are presented in grams.

^d^ Week 1 mean body weights represent body weights taken on the day of weaning.

^e^ Week 12 mean body weights represent body weights taken before rats in all exposure groups were moved to metabolic cages for 16 hours during week 13.

Figure 6

Growth Curves for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) males and (B) females.

In male rats, mean water consumption (mL/animal/day) by the 25 mg/L group was less than that of the control group throughout the entire postweaning period (Table 20; Appendix D). During week 12, mean water consumption by the 25 mg/L group was 62% of that of the control group. The 6.25 and 12.5 mg/L groups had lower mean water consumption compared to the control group for most of the postweaning period, but consumption was similar to the control group in the last week of the study. In female rats, mean water consumption was less than that of the control group throughout the entire postweaning period for groups exposed to ≥6.25 mg/L (Table 20). During week 12, mean water consumption by the 6.25 and 12.5 mg/L groups was 91% and 82%, respectively, of that of the control group (not significantly different). During week 12, mean water consumption by the 25 mg/L was 58% of that of the control group.

Table 20 Summary of Water and Nicotine Bitartrate Dihydrate Consumption by Male and Female Rats in the Perinatal and Three-month Drinking Water Study^a^

Week | 0 mg/L | | 1.56 mg/L | | 3.12 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L
Week | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
Water (mL/animal/day)^b,c^
1 | 28.3 ± 1.9 | 10 | 24.3 ± 1.0 | 10 | 28.0 ± 4.1 | 10 | 23.8 ± 1.5* | 10 | 23.5 ± 0.6* | 10 | 19.5 ± 2.5** | 10
12^d^ | 39.0 ± 3.6 | 10 | 40.8 ± 4.6 | 10 | 41.6 ± 4.5 | 10 | 39.3 ± 3.2 | 10 | 35.8 ± 4.0 | 10 | 24.1 ± 2.1** | 10
Chemical Intake (mg/kg/day)^e,f,g^
1–12 | 0 | 10 | 0.2 | 10 | 0.4 | 10 | 0.8 | 10 | 1.5 | 10 | 2.3 | 10
Female
Water (mL/animal/day)^b,c^
1 | 26.3 ± 2.1 | 10 | 24.9 ± 1.4 | 10 | 24.1 ± 3.7 | 10 | 20.7 ± 2.8* | 10 | 20.8 ± 1.9* | 10 | 15.6 ± 1.3** | 10
12^d^ | 29.6 ± 1.8 | 10 | 32.8 ± 3.0 | 10 | 30.8 ± 3.8 | 10 | 26.8 ± 4.8 | 10 | 24.3 ± 2.3 | 10 | 17.2 ± 1.8** | 10
Chemical Intake (mg/kg/day)^e,f,g^
1–12 | 0 | 10 | 0.2 | 10 | 0.5 | 10 | 0.8 | 10 | 1.5 | 10 | 2.2 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation.

^d^ Week 12 mean water consumption represents water consumption taken before rats in all exposure groups were moved to metabolic cages for 16 hours during week 13.

^e^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^f^ No statistical analysis performed on the chemical intake data.

^g^ Milligrams of freebase (-)-nicotine consumed/kg body weight/day.

In male rats, mean feed consumption on study day 1 was lower for all exposed groups compared to the control group (Appendix D), with consumption by the 25 mg/L group at 62% of that of the control group. By week 3, however, mean feed consumption by the 25 mg/L group was 90% of that of the control group and was similar to the control group for the remainder of the study (Table 21; Appendix D). Mean feed consumption by other exposed groups was sporadically less than that of the control group, but the differences were slight and not consistent throughout the study. Therefore, these differences were not considered biologically or toxicologically relevant.

Table 21 Summary of Feed Consumption by Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Week^b,c^ | 0 mg/L | | 1.56 mg/L | | 3.12 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L
Week^b,c^ | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
Feed (g/animal/day)
1 | 20.6 ± 1.1 | 10 | 19.1 ± 1.4 | 10 | 18.7 ± 0.7 | 10 | 17.7 ± 1.1 | 10 | 17.2 ± 1.1 | 10 | 17.7 ± 1.7 | 10
12^d^ | 25.3 ± 0.5 | 10 | 27.1 ± 4.8 | 10 | 27.7 ± 3.1 | 10 | 27.2 ± 1.6 | 10 | 26.2 ± 0.8 | 10 | 23.8 ± 2.0 | 10
Female
Feed (g/animal/day)
1 | 17.1 ± 1.3 | 10 | 15.4 ± 1.2 | 10 | 15.3 ± 2.6 | 10 | 14.8 ± 1.5 | 10 | 14.2 ± 1.1 | 10 | 14.2 ± 0.6 | 10
12^d^ | 17.4 ± 0.1 | 10 | 18.8 ± 2.3 | 10 | 16.6 ± 3.6 | 10 | 18.8 ± 3.3 | 10 | 17.9 ± 2.8 | 10 | 16.3 ± 2.4 | 10

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Data are presented as mean ± standard deviation.

^c^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant findings were noted at p ≤ 0.05.

^d^ Week 12 mean feed consumption represents feed consumption taken before rats in all exposure groups were moved to metabolic cages for 16 hours during week 13.

In female rats, mean feed consumption by the 25 mg/L group was less than that of the control group, although the largest differences were found early in the study; by week 5, mean feed consumption reached 94% of that of the control group (Table 21; Appendix D). Mean feed consumption by the 12.5 mg/L group also was less than that of the control group throughout most of the study, but the differences were less than those of the 25 mg/L group. Other exposed groups had sporadic differences in mean feed consumption, but these were not considered biologically or toxicologically relevant.

At the end of the 3-month study, there were several significant changes observed in both the clinical chemistry and hematology measurements in males and females. These changes were mild, not exposure related, not consistent between species or sex, or lacked biological significance. Thus, none of the observed significant changes were considered related to NBD exposure. There were no marked changes in urinalysis measures that were considered biologically significant (Appendix D).

In male rats, some sporadic and non-significant reductions in mean absolute organ weights (<90% of that of the control group) were accompanied by lower mean relative organ weights; these included the liver of the 25 mg/L group; the adrenal glands of the 3.12, 6.25, and 12.5 mg/L groups; and the urinary bladder and prostate (combined) of the 1.56, 3.12, and 25 mg/L groups (Table 22). In female rats, the mean absolute liver weight of the 25 mg/L group was 86% of that of the control group. However, the mean relative liver weight was unchanged from that of the control male and female rats in the presence of significant body weight decreases. In addition, several organs had non-significantly higher absolute weights ≥110% of that of the control group; these included the spleen of the 1.56 mg/L group; the adrenal glands and uterus of all exposed groups; and the ovaries of the 1.56, 12.5, and 25 mg/L groups (Table 22).

Table 22 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a,b,c^

| 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Terminal Body Wt. (g) | 494.40 ± 31.05 | 493.00 ± 35.46 | 491.50 ± 36.57 | 480.30 ± 27.19 | 463.80 ± 28.58 | 447.40 ± 27.53**
Liver
Absolute (g) | 15.423 ± 1.581 | 14.859 ± 1.902 | 15.749 ± 1.640 | 14.830 ± 1.341 | 14.224 ± 1.750 | 13.806 ± 1.451
Relative (mg/g)^d^ | 31.141 ± 1.667 | 30.068 ± 2.242 | 32.006 ± 1.715 | 30.867 ± 1.957 | 30.586 ± 2.056 | 30.839 ± 2.389
Adrenal Glands
Absolute (g) | 0.078 ± 0.023 | 0.081 ± 0.021 | 0.070 ± 0.010 | 0.065 ± 0.017 | 0.065 ± 0.013 | 0.077 ± 0.021
Relative (mg/g) | 0.159 ± 0.045 | 0.164 ± 0.041 | 0.143 ± 0.027 | 0.136 ± 0.034 | 0.140 ± 0.029 | 0.174 ± 0.052
Urinary Bladder and Prostate (Combined)
Absolute (g) | 0.901 ± 0.242 | 0.789 ± 0.226 | 0.750 ± 0.139 | 0.854 ± 0.093 | 0.861 ± 0.206 | 0.727 ± 0.148
Relative (mg/g) | 1.821 ± 0.477 | 1.606 ± 0.446 | 1.537 ± 0.325 | 1.784 ± 0.229 | 1.858 ± 0.444 | 1.629 ± 0.352
Heart
Absolute (g) | 1.477 ± 0.059 | 1.520 ± 0.102 | 1.470 ± 0.082 | 1.461 ± 0.094 | 1.371 ± 0.086 | 1.367 ± 0.119*
Relative (mg/g) | 2.997 ± 0.203 | 3.094 ± 0.243 | 2.998 ± 0.157 | 3.049 ± 0.226 | 2.959 ± 0.161 | 3.059 ± 0.234
Female
Terminal Body Wt. (g) | 302.40 ± 19.41 | 297.40 ± 21.57 | 284.60 ± 15.32 | 283.80 ± 19.01 | 287.30 ± 20.45 | 273.20 ± 11.50**
Liver
Absolute (g) | 10.595 ± 0.917 | 10.204 ± 1.195 | 9.934 ± 0.983 | 9.808 ± 0.930 | 9.920 ± 0.876 | 9.148 ± 0.911**
Relative (mg/g) | 35.018 ± 1.689 | 34.264 ± 2.580 | 34.860 ± 2.213 | 34.548 ± 2.275 | 34.543 ± 1.975 | 33.461 ± 2.744
Adrenal Glands
Absolute (g) | 0.072 ± 0.011 | 0.084 ± 0.017 | 0.084 ± 0.018 | 0.083 ± 0.026 | 0.096 ± 0.022 | 0.089 ± 0.016
Relative (mg/g) | 0.239 ± 0.037 | 0.285 ± 0.058 | 0.294 ± 0.063 | 0.292 ± 0.086 | 0.336 ± 0.081** | 0.324 ± 0.058*
Spleen
Absolute (g) | 0.546 ± 0.055 | 0.624 ± 0.064 | 0.582 ± 0.112 | 0.579 ± 0.065 | 0.599 ± 0.053 | 0.554 ± 0.062
Relative (mg/g) | 1.808 ± 0.184 | 2.100 ± 0.198 | 2.044 ± 0.361 | 2.040 ± 0.185 | 2.088 ± 0.150 | 2.033 ± 0.262
Uterus
Absolute (g) | 0.527 ± 0.069 | 0.595 ± 0.105 | 0.601 ± 0.169 | 0.610 ± 0.147 | 0.706 ± 0.185 | 0.595 ± 0.169
Relative (mg/g) | 1.756 ± 0.293 | 2.014 ± 0.380 | 2.111 ± 0.556 | 2.153 ± 0.524 | 2.456 ± 0.612* | 2.183 ± 0.638
Ovaries
Absolute (g) | 0.150 ± 0.030 | 0.174 ± 0.041 | 0.159 ± 0.024 | 0.160 ± 0.037 | 0.168 ± 0.033 | 0.169 ± 0.026
Relative (mg/g) | 0.496 ± 0.104 | 0.586 ± 0.140 | 0.560 ± 0.087 | 0.561 ± 0.116 | 0.589 ± 0.140 | 0.619 ± 0.093

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard deviation.

^b^ Statistical analysis performed with the Dunnett (pairwise) test.

^c^ Concentrations in drinking water refer to freebase (-)-nicotine.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

#### Histopathology

This section describes incidences of select nonneoplastic lesions in the kidney, larynx, mandibular lymph node, stomach, large and small intestines, pancreas, Harderian gland, testes, and salivary glands. Multiple organ systems exhibited minimal to mild focal inflammation or changes in lymphoid tissues that did not follow any consistent dose response, making associations with exposures uncertain.

Kidney: Minimal focal or mild diffuse inflammation in the kidney was present in exposed male and female rats and control rats (Table 23). One male rat in the 25 mg/L group and one female rat in the 12.5 mg/L group also had hyperplasia of the transitional epithelium of the pelvis (Appendix D).

Table 23 Incidences of Select Nonneoplastic Lesions in Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

| 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
n^b^ | 10 | 10 | 10 | 10 | 10 | 10
Male
Kidney
Inflammation, focal, minimal^c^ | 3 | 5 | 3 | 5 | 9** | 3
Inflammation, diffuse, mild | 0 | 1 | 0 | 0 | 0 | 0
Larynx
Inflammation, minimal | 0 | 2 | 1 | 2 | 2 | 3
Lymph Node, Mandibular
Lymphadenitis, chronic reactive, minimal | 2 | 5 | 4 | 4 | 2 | 8*
Stomach, Forestomach
Hyperkeratosis, minimal | 0 | 0 | 0 | 2 | 3 | 0
Intestine, Large, Rectum
Inflammation, minimal | 1 | 1 | 5 | 1 | 2 | 2
Intestine Small, Duodenum
Inflammation, minimal | 2 | 2 | 2 | 1 | 0 | 1
Pancreas
Inflammation, focal, minimal | 1 | 2 | 1 | 0 | 2 | 1
Harderian Gland
Inflammation, focal, minimal | 1 | 1 | 1 | 0 | 0 | 1
Testes
Degeneration, fibrosis tubules | 0 | 0 | 0 | 0 | 1 | 0
Degeneration, seminiferous tubules, minimal | 0 | 0 | 0 | 0 | 1 | 1
Degeneration, germinal epithelium, mild | 0 | 0 | 0 | 0 | 0 | 1
Mineralization, tubules, minimal | 0 | 0 | 0 | 0 | 1 | 1
Hyperplasia, interstitial cells | 0 | 0 | 0 | 0 | 0 | 1
Salivary Glands
Inflammation, focal, minimal | 1 | 2 | 1 | 3 | 0 | 1
Female
Kidney
Inflammation, focal, minimal | 2 | 1 | 4 | 5 | 5 | 2
Inflammation, diffuse, mild | 0 | 0 | 0 | 0 | 1 | 1
Larynx
Inflammation, minimal | 0 | 0 | 0 | 1 | 4 | 1
Lymph Node, Mandibular
Lymphadenitis, chronic, reactive, minimal | 3 | 4 | 3 | 3 | 2 | 7
Stomach, Forestomach
Hyperkeratosis, minimal | 0 | 0 | 0 | 1 | 0 | 0
Intestine, Large, Rectum
Inflammation, minimal | 0 | 3 | 0 | 4 | 2 | 2
Intestine Small, Duodenum
Inflammation, minimal | 0 | 0 | 1 | 0 | 3 | 1
Pancreas
Inflammation, focal, minimal | 0 | 2 | 2 | 0 | 0 | 4
Harderian Gland
Inflammation, focal, minimal | 1 | 4 | 1 | 4 | 3 | 2
Salivary Glands
Inflammation, focal, minimal | 0 | 0 | 1 | 0 | 0 | 1

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control.

* Statistically significant at p ≤ 0.05 by Fisher’s exact test; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

Larynx: Minimal inflammation of the larynx was present in all exposed male rat groups (Table 23). Similarly, in exposed female rat groups, minimal laryngeal inflammation was present at exposure concentrations of ≥6.25 mg/L. These lesions were not considered biologically significant.

Mandibular lymph node: The incidence of minimal chronic reactive lymphadenitis was higher in most of the exposed male groups than in the control group and was significantly increased in the 25 mg/L group (Table 23). A similar pattern was apparent in female rats, with minimal chronic reactive lymphadenitis present in seven rats in the 25 mg/L group compared to three rats in the control group.

Stomach: Minimal hyperkeratosis of the forestomach was observed at 6.25 and 12.5 mg/L in males and at 6.25 mg/L in females (Table 23).

Large and small intestines: Higher incidences of minimal inflammation of the rectum were present in males from the 3.12, 12.5, and 25 mg/L groups, and females in the 1.56, 6.25, 12.5, and 25 mg/L groups, compared to respective control groups (Table 23). Minimal inflammation of the duodenum was observed in females in the 3.12, 12.5, and 25 mg/L groups but not in control females (Table 23). This lesion was also observed in exposed males but at incidences that did not exceed that of the control group.

Pancreas: Minimal focal inflammation of the pancreas was observed in female rats in the 1.56, 3.12, and 25 mg/L groups but not in control females (Table 23). This lesion was observed in male rats at each exposure concentration, except 6.25 mg/L, and was observed in one rat in the control group.

Harderian gland: Minimal focal inflammation was increased in all but the 3.12 mg/L exposed group of females compared to control females (Table 23). This lesion was not increased in male rats.

Testes: Degenerative lesions of the testes were observed in two rats in the two highest exposed groups (Table 23). There was a positive trend for the incidence of rats bearing lesions.

Salivary glands: Minimal focal inflammation was observed in all but the 12.5 mg/L group of males, including in one rat in the control group (Table 23). Single instances were observed in the 3.12 and 25 mg/L female groups.

## Mice

### Four-week Dose Range-finding Study

All mice survived until study termination, and no clinical observations recorded during the study were considered exposure related (Table 24; Appendix D).

Table 24 Summary of Survival, Mean Body Weights, and Body Weight Gains of Male and Female Mice in the Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate, with Two-week Recovery Period^a^

Study Day^b,c^ | 0 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L | | 50 mg/L | | 100 mg/L
Study Day^b,c^ | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n | Av. Wt. (g) | n
Male
Exposure Period
0 | 41.3 ± 2.7 | 20 | 41.1 ± 3.7 | 10 | 42.8 ± 2.8 | 10 | 40.6 ± 4.4 | 10 | 41.8 ± 3.7 | 10 | 40.5 ± 3.5 | 20
1^d,e^ | 41.8 ± 2.2 | 20 | 41.8 ± 3.6 | 10 | 43.3 ± 2.6 | 10 | 41.8 ± 4.1 | 10 | 43.2 ± 3.7 | 10 | 41.8 ± 3.5 | 20
3^e^ | 42.4 ± 2.5 | 20 | 42.5 ± 4.0 | 10 | 44.0 ± 2.6 | 10 | 42.4 ± 4.0 | 10 | 43.8 ± 3.7 | 10 | 41.7 ± 3.8 | 20
7^e^ | 43.0 ± 2.4 | 20 | 42.2 ± 4.2 | 10 | 44.7 ± 2.9 | 10 | 42.6 ± 4.2 | 10 | 43.4 ± 4.0 | 10 | 42.2 ± 3.9 | 20
14^e^ | 43.0 ± 2.4 | 20 | 43.0 ± 3.8 | 10 | 44.2 ± 3.1 | 10 | 42.5 ± 4.0 | 10 | 43.6 ± 3.6 | 10 | 42.5 ± 4.0 | 20
21 | 44.9 ± 3.0 | 20 | 43.7 ± 4.1 | 10 | 45.2 ± 2.9 | 10 | 44.0 ± 4.9 | 10 | 44.4 ± 3.7 | 10 | 43.3 ± 4.5 | 20
28^f^ | 44.5 ± 3.2 | 20 | 41.7 ± 4.6 | 10 | 42.6 ± 3.3 | 10 | 41.9 ± 6.3 | 10 | 42.1 ± 4.1 | 10 | 43.4 ± 3.9 | 20
Recovery Period^g^
35 | 44.7 ± 2.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 43.4 ± 3.6 | 10
42^e,f^ | 45.6 ± 2.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 43.6 ± 4.9 | 10
Weight Change
0–21 | 3.6 ± 1.0 | 20 | 2.6 ± 1.2 | 10 | 2.4 ± 1.5 | 10 | 3.4 ± 1.3 | 10 | 2.6 ± 1.4 | 10 | 2.8 ± 2.1 | 20
Female
Exposure Period
0 | 33.8 ± 3.1 | 20 | 33.4 ± 2.2 | 10 | 33.4 ± 2.9 | 10 | 31.4 ± 2.8 | 10 | 33.2 ± 3.7 | 10 | 33.4 ± 3.3 | 20
1^d,e^ | 33.8 ± 3.3 | 20 | 34.4 ± 2.3 | 10 | 33.2 ± 2.6 | 10 | 31.1 ± 2.9 | 10 | 33.5 ± 3.2 | 10 | 34.4 ± 3.8 | 20
3^e^ | 33.6 ± 3.0 | 20 | 34.9 ± 2.1 | 10 | 33.9 ± 2.6 | 10 | 32.0 ± 2.8 | 10 | 33.3 ± 3.0 | 10 | 33.8 ± 3.5 | 20
7^e^ | 34.7 ± 3.0 | 20 | 35.1 ± 3.2 | 10 | 34.7 ± 2.7 | 10 | 32.4 ± 3.6 | 10 | 33.1 ± 3.1 | 10 | 34.6 ± 3.5 | 20
14^e^ | 34.8 ± 3.6 | 20 | 35.0 ± 3.5 | 10 | 34.9 ± 3.3 | 10 | 32.1 ± 2.9 | 10 | 34.5 ± 3.6 | 10 | 35.1 ± 3.9 | 20
21 | 35.1 ± 2.9 | 20 | 36.8 ± 3.1 | 10 | 35.6 ± 2.6 | 10 | 33.3 ± 2.7 | 10 | 34.5 ± 3.7 | 10 | 35.8 ± 4.0 | 20
28^f^ | 34.8 ± 3.5 | 20 | 34.5 ± 3.7 | 10 | 33.8 ± 2.1 | 10 | 32.3 ± 3.8 | 10 | 33.2 ± 3.2 | 10 | 34.1 ± 3.5 | 20
Recovery Period^g^
35 | 36.2 ± 3.7 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 35.6 ± 2.7 | 10
42^e,f^ | 37.4 ± 3.5 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 36.5 ± 3.6 | 10
Weight Change
0–21 | 1.4 ± 1.5 | 20 | 3.1 ± 2.2 | 10 | 2.2 ± 1.8 | 10 | 1.9 ± 2.2 | 10 | 1.3 ± 1.1 | 10 | 2.4 ± 1.8 | 20

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Data are presented as mean ± standard deviation. Body weight data are presented in grams.

^d^ Study day 1 is the day animals were placed on study.

^e^ No statistical analysis performed on this endpoint.

^f^ On study day 28, measurements were taken after 10 mice from each exposure group were moved to metabolic cages for 16 hours. On study day 42 (recovery period), measurements were taken after 10 mice each from the control and 100 mg/L groups were moved to metabolic cages for 16 hours.

^g^ Data for the recovery period were collected for only 10 mice in the control group and 100 mg/L group.

Mean body weights of all exposed groups of male and female mice were within 10% of those of the control groups throughout the study (Table 24; Figure 7). At the end of exposure, mean body weights of the 100 mg/L male and female groups were within 5% of the respective control groups.

Figure 7

Growth Curves for Male and Female Mice in the Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) males and (B) females.

In male mice, mean water consumption (mL/animal/day) by all exposed groups fluctuated throughout the study compared to the control group, with consumption as low as 79% on study day 21 for the 100 mg/L group (Table 25). A similar pattern was observed in female mice, wherein mean water consumption by the 100 mg/L group was 79% of that of the control group on study day 21. None of the reductions in water consumption were significant. Mean water consumption by the 100 mg/L male and female recovery groups was approximately 95% and 112%, respectively, of that of the control groups.

Table 25 Summary of Water and Nicotine Bitartrate Dihydrate Consumption by Male and Female Mice in the Four-week Dose Range-finding Drinking Water Study, with Two-week Recovery Period^a^

Study Day | 0 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L | | 50 mg/L | | 100 mg/L
Study Day | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
Water (mL/animal/day)^b,c^
Exposure Period
0 | 7.0 ± 0.5 | 20 | 6.2 ± 1.4 | 10 | 6.0 ± 0.6 | 10 | 6.6 ± 0.3 | 10 | 6.4 ± 1.1 | 10 | 6.8 ± 0.7 | 20
1^d^ | 7.3 ± 0.8 | 20 | 6.2 ± 0.8 | 10 | 6.8 ± 0.6 | 10 | 7.0 ± 0.8 | 10 | 6.8 ± 0.6 | 10 | 6.8 ± 0.6 | 20
21 | 7.1 ± 0.8 | 20 | 6.0 ± 1.1 | 10 | 6.4 ± 1.1 | 10 | 6.0 ± 1.1 | 10 | 6.2 ± 0.3 | 10 | 5.6 ± 0.6 | 20
28^e^ | 7.2 ± 0.6 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 7.8 ± 0.3 | 10
Recovery Period^f^
35 | 7.8 ± 0.3 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 7.4 ± 1.4 | 10
Chemical Intake (mg/kg/day)^g^
0–21 | 0 | 20 | 1 | 10 | 2 | 10 | 3.8 | 10 | 7.6 | 10 | 14 | 20
Female
Water (mL/animal/day)^b,c^
Exposure Period
0 | 6.5 ± 0.5 | 20 | 6.2 ± 0.3 | 10 | 5.4 ± 0.3 | 10 | 5.8 ± 1.4 | 10 | 6.2 ± 0.8 | 10 | 6.1 ± 0.4 | 20
1^d^ | 6.9 ± 0.8 | 20 | 6.8 ± 1.1 | 10 | 6.6 ± 0.3 | 10 | 7.2 ± 1.7 | 10 | 6.2 ± 0.8 | 10 | 6.4 ± 0.5 | 20
21 | 6.3 ± 0.9 | 20 | 5.2 ± 0.0 | 10 | 6.2 ± 0.3 | 10 | 6.0 ± 0.0 | 10 | 5.4 ± 0.3 | 10 | 5.0 ± 0.8 | 20
28^e^ | 8.0 ± 2.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 8.0 ± 1.7 | 10
Recovery Period^f^
35 | 6.6 ± 0.8 | 10 | – | 0 | – | 0 | – | 0 | – | 0 | 7.4 ± 1.4 | 10
Chemical Intake (mg/kg/day)^g^
0–21 | 0 | 20 | 1.2 | 10 | 2.4 | 10 | 5.0 | 10 | 9.1 | 10 | 15.3 | 20

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant differences were identified at p ≤ 0.05.

^c^ Data are presented as mean ± standard deviation.

^d^ Study day 1 is the day animals were placed on study.

^e^ For study day 28, measurements are reported for only 10 mice each in the control and 100 mg/L recovery groups.

^f^ Data for the recovery period were collected for only 10 mice each in the control group and 100 mg/L group.

^g^ Milligrams of nicotine bitartrate dihydrate consumed/kg body weight/day.

Throughout the study, mean feed consumption by exposed groups was similar to that of the control groups for both male and female mice. While sporadic differences from the control group were found, they were not consistent and did not indicate an exposure-related effect (Appendix D).

No clinical chemistry or hematological changes were observed in exposed male or female mice compared to control mice (Appendix D).

In female mice, mean absolute weights of the thymus and mediastinal lymph nodes (combined), adrenal glands, uterus, and ovaries were lower in all exposed groups compared to those of the control group (Table 26). However, there were no significant exposure concentration-related decreases in organ weights. The mean absolute weight of the adrenal glands in the exposed groups was 67%–80% of that of the control group, but the mean weight in the control group was higher than that recorded in the female recovery control group (Appendix D). In fact, the mean absolute weight of the adrenal glands in the 100 mg/L recovery group was 145% of that of the recovery control group. These observations, along with other sporadic differences in mean organ weights, were not considered toxicologically relevant because they lacked consistency, exposure concentration-related response, and histopathological correlations.

Table 26 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Female Mice in the Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a,b,c^

| 0 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L | 50 mg/L | 100 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Terminal Body Wt. (g) | 33.50 ± 3.06 | 34.50 ± 3.75 | 33.80 ± 2.10 | 32.30 ± 3.80 | 33.20 ± 3.22 | 34.40 ± 4.17
Thymus and Mediastinal Lymph Nodes (Combined)
Absolute (g) | 0.052 ± 0.022 | 0.041 ± 0.014 | 0.042 ± 0.009 | 0.042 ± 0.013 | 0.049 ± 0.010 | 0.049 ± 0.009
Relative (mg/g)^d^ | 1.531 ± 0.512 | 1.201 ± 0.431 | 1.253 ± 0.277 | 1.306 ± 0.374 | 1.476 ± 0.305 | 1.422 ± 0.186
Adrenal Glands
Absolute (g) | 0.015 ± 0.008 | 0.010 ± 0.007 | 0.012 ± 0.005 | 0.012 ± 0.007 | 0.011 ± 0.002 | 0.012 ± 0.005
Relative (mg/g) | 0.431 ± 0.206 | 0.293 ± 0.164 | 0.344 ± 0.140 | 0.377 ± 0.255 | 0.325 ± 0.052 | 0.363 ± 0.134
Uterus
Absolute (g) | 0.230 ± 0.075 | 0.189 ± 0.059 | 0.171 ± 0.080 | 0.161 ± 0.064 | 0.175 ± 0.080 | 0.212 ± 0.091
Relative (mg/g) | 6.898 ± 2.312 | 5.558 ± 1.864 | 5.060 ± 2.431 | 4.888 ± 1.382 | 5.258 ± 2.256 | 6.300 ± 2.913
Ovaries
Absolute (g) | 0.063 ± 0.019 | 0.055 ± 0.016 | 0.059 ± 0.024 | 0.054 ± 0.029 | 0.050 ± 0.016 | 0.058 ± 0.021
Relative (mg/g) | 1.861 ± 0.493 | 1.633 ± 0.523 | 1.746 ± 0.654 | 1.648 ± 0.788 | 1.518 ± 0.470 | 1.695 ± 0.591

^a^ Data are presented as mean ± standard deviation.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Concentrations in drinking water refer to freebase (-)-nicotine.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight per g body weight.

Likewise, in male mice, there were sporadic occurrences of organ weights being <90% or >110% of those of the control group. None of the occurrences were consistent, exhibited a pattern of exposure-concentration relatedness, or had histopathological correlations; thus, they were not considered toxicologically relevant. These observations were true for both the 4-week study groups and the recovery groups (Appendix D).

#### Histopathology

This section describes the incidences of select nonneoplastic lesions in the kidney, intestines (all sites), liver, and Harderian gland. The incidences were not statistically significant. The control and 100 mg/L groups were the only groups examined microscopically.

Kidney: Minimal focal inflammation of the kidney was present in exposed and control male and female mice, and moderate diffuse inflammation was diagnosed in one exposed male (Table 27).

Table 27 Incidences of Select Nonneoplastic Lesions in Male and Female Mice in the Four-week Dose Range-finding Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

| 0 mg/L | 100 mg/L
n^b^ | 10 | 10
Male^c^
Kidney
Inflammation, focal, minimal^d^ | 1 | 4
Inflammation, diffuse, moderate | 0 | 1
Intestines (All Sites)
Inflammation, minimal | 4 | 6
Harderian Gland
Inflammation, focal, minimal | 0 | 1
Female
Kidney
Inflammation, focal, minimal | 1 | 1
Stomach, Glandular
Inflammation, focal | 0 | 1
Intestines (All Sites)
Inflammation, minimal | 3 | 2
Liver
Necrosis, focal, minimal, with inflammation | 0 | 3
Harderian Gland
Inflammation, focal, minimal | 0 | 3

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Number of animals examined microscopically.

^c^ The exposed group was compared to the vehicle control group with Fisher’s exact (pairwise) test. No statistically significant differences were identified at p ≤ 0.05.

^d^ Number of animals with lesion.

Stomach and intestines (all sites): In exposed and control male and female mice, inflammation was present (Table 27).

Liver: Minimal focal necrosis with inflammation was present in three female mice in the 100 mg/L group but was considered a background lesion (Table 27). The lesion consisted of one or several small areas of necrosis with an associated mixed inflammatory cell response.

Harderian gland: Minimal focal inflammation was present in exposed male and female mice (Table 27). This lesion was not observed in control mice.

### Exposure Concentration Selection Rationale for the Three-month Study

The 4-week study informed selection of exposure concentrations for the 3-month study in mice. Exposure to drinking water solutions with NBD ≤100 mg/L for 4 weeks was well tolerated, and therefore the exposure concentrations selected for the 3-month study in mice were the same as the 4-week study (0, 6.25, 12.5, 25, 50, and 100 mg/L).

### Three-month Study

All mice survived until study termination, and no clinical observations recorded during the study were considered exposure related (Appendix D).

Mean body weights of all exposed groups of male and female mice were within 10% of those of the control groups throughout the study (Table 28; Figure 8). At study termination, mean body weights of the 100 mg/L male and female groups were approximately 93% and 95% of those of their respective control groups.

Table 28 Summary of Survival, Mean Body Weights, and Body Weight Gains of Male and Female Mice in the Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

Week^b,c^ | 0 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L | | 50 mg/L | | 100 mg/L
Week^b,c^ | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
1^d^ | 40.4 ± 2.8 | 30 | 40.4 ± 3.2 | 15 | 40.6 ± 2.4 | 15 | 39.7 ± 3.4 | 15 | 42.3 ± 3.6 | 15 | 40.2 ± 3.1 | 30
12^e^ | 46.0 ± 3.9 | 30 | 47.1 ± 5.2 | 15 | 44.5 ± 3.7 | 15 | 45.1 ± 5.2 | 15 | 45.5 ± 3.2 | 15 | 42.9 ± 4.1* | 30
Weight Change
1–12 | 5.7 ± 2.6 | 30 | 6.7 ± 2.6 | 15 | 3.9 ± 2.2 | 15 | 5.5 ± 3.4 | 15 | 3.1 ± 2.1** | 15 | 2.7 ± 2.1** | 30
Female
1^d^ | 31.6 ± 3.5 | 30 | 31.8 ± 3.2 | 15 | 31.4 ± 3.4 | 15 | 29.9 ± 2.7 | 15 | 32.1 ± 2.5 | 15 | 31.0 ± 3.5 | 30
12^e^ | 38.6 ± 5.7 | 30 | 37.9 ± 4.8 | 15 | 37.7 ± 5.2 | 15 | 37.6 ± 4.6 | 15 | 37.3 ± 3.3 | 15 | 36.8 ± 4.8 | 30
Weight Change
1–12 | 7.0 ± 3.5 | 30 | 6.1 ± 3.1 | 15 | 6.3 ± 2.7 | 15 | 7.7 ± 2.7 | 15 | 5.2 ± 2.0 | 15 | 5.8 ± 2.2 | 30

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation. Body weight data are presented in grams.

^d^ Week 1 mean body weights represent body weights taken the day prior to study start.

^e^ Week 12 mean body weights represent body weights taken before mice in all exposure groups were moved to metabolic cages for 16 hours during week 13.

Figure 8

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate

Growth curves are shown for (A) males and (B) females.

In male mice, mean water consumption (mL/animal/day) by the 100 mg/L group was <90% of that of the control group for most of the first half of the study, as well as for the last 3 weeks (Table 29). Other exposed groups had sporadic weeks with water consumption less than that of the control group, but they were not consistent or considered biologically or toxicologically significant. In female mice, beginning on study day 1, mean water consumption was <90% of that of the control group by all exposed groups for most of the study. The largest differences were in the 100 mg/L group, which had mean water consumption <80% of that of the control group during most weeks.

Table 29 Summary of Water and Nicotine Bitartrate Dihydrate Consumption by Male and Female Mice in the Three-month Drinking Water Study^a^

Week | 0 mg/L | | 6.25 mg/L | | 12.5 mg/L | | 25 mg/L | | 50 mg/L | | 100 mg/L
Week | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n | Av. | n
Male
Water (mL/animal/day)^b,c^
1^d^ | 7.7 ± 0.7 | 30 | 7.6 ± 0.8 | 15 | 7.3 ± 0.5 | 15 | 8.1 ± 0.9 | 15 | 8.0 ± 1.1 | 15 | 7.3 ± 0.9 | 30
12^e^ | 7.4 ± 0.9 | 30 | 7.3 ± 0.9 | 15 | 7.3 ± 0.6 | 15 | 8.1 ± 1.6 | 15 | 7.6 ± 1.1 | 15 | 6.4 ± 0.5 | 30
Chemical Intake (mg/kg/day)^f^
1–12 | 0 | 30 | 1 | 15 | 2 | 15 | 4.4 | 15 | 8.1 | 15 | 15 | 30
Female
Water (mL/animal/day)^b,c^
1^d^ | 7.9 ± 1.4 | 30 | 7.3 ± 1.2 | 15 | 7.7 ± 0.8 | 15 | 7.1 ± 1.2 | 15 | 8.1 ± 2.0 | 15 | 8.1 ± 1.3 | 30
12^e^ | 8.1 ± 0.9 | 30 | 7.3 ± 0.8 | 15 | 7.7 ± 0.8 | 15 | 7.5 ± 1.3 | 15 | 7.2 ± 0.8 | 15 | 5.9 ± 0.3** | 30
Chemical Intake (mg/kg/day)^f^
1–12 | 0 | 30 | 1.4 | 15 | 2.4 | 15 | 5.1 | 15 | 9.6 | 15 | 18.6 | 30

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01.

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett test.

^c^ Data are presented as mean ± standard deviation.

^d^ Week 1 mean water consumption represents water consumption taken the day prior to study start.

^e^ Week 12 mean water consumption represents water consumption taken before mice in all exposure groups were moved to metabolic cages for 16 hours during week 13.

^f^ Milligrams of nicotine bitartrate dihydrate consumed/kg body weight/day.

Throughout the study, mean feed consumption by the exposed groups was similar to that of the control groups for both male and female mice. Sporadic differences from the control groups were neither consistent nor related to exposure concentrations and did not indicate an exposure-related effect (Appendix D).

At the end of the 3-month study, there were some significant changes observed in both the clinical chemistry and hematology measures from male and female mice. These changes were mild, not exposure related, not consistent between species or sex, or lacked biological significance. Thus, none of the observed significant changes were considered related to NBD exposure. In exposed groups of mice, mean absolute and relative weights of the adrenal glands in males and of the spleen and thymus in females were <90% of that of the control group; however, changes were not significant (Table 30; Appendix D).

Table 30 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male and Female Mice in the Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a,b,c^

| 0 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L | 50 mg/L | 100 mg/L
n | 15 | 15 | 15 | 15 | 15 | 15
Male
Terminal Body Wt. (g) | 40.07 ± 3.01 | 41.33 ± 4.95 | 39.07 ± 3.26 | 39.00 ± 4.64 | 39.13 ± 2.53 | 38.07 ± 3.01
Adrenal Glands
Absolute (g) | 0.013 ± 0.014 | 0.008 ± 0.007 | 0.007 ± 0.002 | 0.009 ± 0.009 | 0.007 ± 0.003 | 0.010 ± 0.007
Relative (mg/g)^d^ | 0.311 ± 0.343 | 0.197 ± 0.165 | 0.179 ± 0.064 | 0.233 ± 0.189 | 0.170 ± 0.073 | 0.265 ± 0.198
Seminal Vesicles and Coagulating Gland
Absolute (g) | 0.456 ± 0.106 | 0.435 ± 0.125 | 0.472 ± 0.165 | 0.459 ± 0.103 | 0.461 ± 0.114 | 0.407 ± 0.056
Relative (mg/g) | 11.362 ± 2.306 | 10.652 ± 3.408 | 12.258 ± 4.965 | 11.822 ± 2.567 | 11.675 ± 2.283 | 10.685 ± 1.287
Female
Terminal Body Wt. (g) | 33.67 ± 4.51 | 34.07 ± 4.64 | 33.13 ± 4.76 | 33.27 ± 4.15 | 32.33 ± 3.13 | 32.60 ± 4.27
Spleen
Absolute (g) | 0.171 ± 0.174 | 0.117 ± 0.027 | 0.114 ± 0.022 | 0.117 ± 0.031 | 0.125 ± 0.061 | 0.121 ± 0.029
Relative (mg/g) | 4.994 ± 4.914 | 3.497 ± 0.952 | 3.463 ± 0.512 | 3.540 ± 0.985 | 3.848 ± 1.717 | 3.698 ± 0.734
Thymus
Absolute (g) | 0.048 ± 0.042 | 0.038 ± 0.016 | 0.037 ± 0.008 | 0.040 ± 0.008 | 0.036 ± 0.016 | 0.038 ± 0.011
Relative (mg/g) | 1.393 ± 1.140 | 1.129 ± 0.437 | 1.109 ± 0.221 | 1.215 ± 0.346 | 1.125 ± 0.448 | 1.174 ± 0.311

^a^ Data are presented as mean ± standard deviation.

^b^ Each exposed group was compared to the vehicle control group with the Dunnett (pairwise) test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Concentrations in drinking water refer to freebase (-)-nicotine.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight per g body weight.

#### Histopathology

This section describes the incidences of select nonneoplastic lesions in the kidney, urinary bladder, stomach, large and small intestines, and Harderian gland. Multiple organ systems exhibited minimal to mild focal inflammation that did not follow any consistent exposure concentration response, making associations with exposures uncertain.

Kidney: A positive trend of mild diffuse inflammation was observed in female treated mice (Table 31).

Table 31 Incidences of Select Nonneoplastic Lesions in Male and Female Mice in the Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a^

| 0 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L | 50 mg/L | 100 mg/L
Male^b^
Kidney^c^ | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal^d^ | 4 | 2 | 2 | 3 | 4 | 5
Inflammation, diffuse, mild | 4 | 1 | 1 | 1 | 1 | 4
Urinary Bladder | 13 | 15 | 15 | 14 | 15 | 15
Inflammation, focal, minimal | 0 | 2 | 1 | 0 | 0 | 0
Stomach, Glandular | 13 | 14 | 15 | 15 | 15 | 14
Inflammation, minimal | 1 | 0 | 2 | 1 | 1 | 0
Intestine, Large, Rectum | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 0 | 1 | 1 | 1 | 2
Intestine, Large, Colon | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 0 | 2 | 1 | 3 | 1
Intestine, Small, Jejunum | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 1 | 0 | 0 | 1 | 0
Intestine, Small, Duodenum | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 0 | 0 | 0 | 2 | 0
Pancreas | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal | 0 | 1 | 0 | 0 | 1 | 0
Harderian Gland | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal | 2 | 1 | 0 | 0 | 1 | 1
Salivary Glands | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, mild | 2 | 6 | 1 | 6 | 5 | 4
Female
Kidney | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal | 1 | 4 | 0 | 2 | 4 | 2
Inflammation, diffuse, mild | 0 | 1 | 0 | 2 | 2 | 3
Urinary Bladder | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal | 0 | 0 | 0 | 2 | 0 | 2
Stomach, Glandular | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 1 | 2 | 4 | 2 | 2
Intestine, Large, Rectum | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 1 | 0 | 1 | 3 | 0
Intestine, Large, Colon | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 2 | 4 | 4 | 1 | 2 | 0
Intestine, Small, Jejunum | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 0 | 1 | 1 | 0 | 0 | 3
Intestine, Small, Duodenum | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, minimal | 1 | 2 | 2 | 0 | 0 | 0
Pancreas | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal | 0 | 0 | 1 | 2 | 2 | 1
Harderian Gland | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, minimal | 1 | 0 | 3 | 2 | 2 | 2
Salivary Glands | 15 | 15 | 15 | 15 | 15 | 15
Inflammation, focal, mild | 5 | 7 | 8 | 9 | 5 | 5

^a^ Concentrations in drinking water refer to freebase (-)-nicotine.

^b^ Each exposed group was compared to the vehicle control group using Fisher’s exact (pairwise) test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Number of animals examined microscopically.

^d^ Number of animals with lesion.

Urinary bladder: Minimal focal inflammation of the urinary bladder was present in two male mice in the 6.25 mg/L group, one male mouse in the 12.5 mg/L group, and two female mice in each of the 25 and 100 mg/L groups (Table 31).

Stomach, glandular: Minimal inflammation of the glandular stomach was present in all exposed groups, but not in the control group, of female mice (Table 31).

Large and small intestines: Minimal inflammation of the colon (males only), rectum (males and females), and duodenum (males only) was observed in only exposed animals, and no cases of inflammation of these tissues were observed in control mice (Table 31). A nonsignificant trend of higher incidence of minimal inflammation of the jejunum was observed in exposed female mice (Table 31). No cases of minimal inflammation of the jejunum were observed in control mice (Table 31).

Harderian gland: Minimal focal inflammation occurred in exposed and control female mice (Table 31).

Salivary glands: Mild focal inflammation occurred to a higher extent in exposed male mice compared to control mice (Table 31).

## Internal Concentration Assessment

Plasma and urine samples from male and female Sprague Dawley rats and Swiss mice were collected after the 3-month studies and were analyzed for nicotine and cotinine and screened for eight metabolites: trans-3’-hydroxy cotinine, (S)-cotinine N-oxide, cotinine N-β-D-glucuronide, (R,S)-norcotinine, (R,S)-nornicotine, trans-3’-hydroxy cotinine O-β-D-glucuronide, (1’S,2’S)-nicotine 1’-oxide, and nicotine N-β-D-glucuronide. For both rats and mice, cotinine concentrations were similar to or higher than nicotine concentrations, and concentrations in urine were higher than in plasma (Table 32, Table 33). In general, the concentrations for both nicotine and cotinine increased with increasing exposure. All control group samples for both species, matrices, and analytes were below the limit of quantitation (LOQ), except for one mouse urine nicotine sample, which was slightly above the LOQ. Creatinine was present in all urine samples and showed some elevation in the higher exposure groups.

Table 32 Summary of Internal Concentration Data for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a,b,c^

| 0 mg/L | 1.56 mg/L | 3.12 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L
n | 5 | 5 | 5 | 5 | 5 | 5
Nicotine Concentration^d^
Male
Plasma (ng/mL) | 1.66 ± 0.784** | 2.14 ± 0.378 | 12.6 ± 5.83** | 9.57 ± 4.56** | 6.14 ± 1.65* | 23.6 ± 10.9**
Urine (ng/mL) | 2.38 ± 0.812** | 299 ± 88.2** | 600 ± 96.8** | 1,070 ± 138** | 1,940 ± 578** | 3,800 ± 658**
Creatinine-adjusted urine (ng/mg) | 3.3 ± 1.1** | 397.0 ± 95.7** | 926.3 ± 222.8** | 1,044.6 ± 121.9** | 1,999.3 ± 466.7** | 3,028.6 ± 501.2**
Female
Plasma (ng/mL) | 0.551 ± 0.101** | 3.22 ± 1.67** | 7.22 ± 2.41** | 5.18 ± 1.31** | 7.68 ± 3.38** | 37.4 ± 12.5**
Urine (ng/mL) | 2.10 ± 0.510** | 247 ± 25.9** | 588 ± 104** | 606 ± 152** | 1,340 ± 375** | 2,920 ± 358**
Creatinine-adjusted urine (ng/mg) | 4.0 ± 0.9** | 500.3 ± 46.3** | 1,303.1 ± 189.5** | 923.6 ± 238.9** | 2,237.4 ± 476.3** | 2,977.5 ± 335.9**
Cotinine Concentration^d^
Male
Plasma (ng/mL) | BD^e^ | 19.0 ± 4.02 | 41.8 ± 11.3 | 41.7 ± 6.81 | 81.2 ± 13.7 | 210 ± 33.4
Urine (ng/mL) | 1.57 ± 0.130** | 337 ± 88.4** | 624 ± 84.6** | 1,030 ± 123** | 2,040 ± 394** | 5,290 ± 763**
Creatinine-adjusted urine (ng/mg) | 2.2 ± 0.2** | 456.7 ± 102.1** | 976.4 ± 238.8** | 1,006.9 ± 98.0** | 2,169.0 ± 304.0** | 4,237.0 ± 605.5**
Female
Plasma (ng/mL) | BD^e^ | 24.5 ± 2.66 | 69.2 ± 8.09 | 59.3 ± 12.3 | 120 ± 12.1 | 259 ± 34.6
Urine (ng/mL) | 2.45 ± 0.168** | 345 ± 36.9** | 737 ± 64.9** | 976 ± 198** | 2,050 ± 299** | 5,840 ± 455**
Creatinine-adjusted urine (ng/mg) | 4.7 ± 0.4** | 705.0 ± 78.2** | 1,679.7 ± 196.5** | 1,485.5 ± 314.1** | 3,528.2 ± 404.1** | 6,014.6 ± 602.7**
Creatinine Concentration^d^
Male
Urine (mg/dL) | 71.8 ± 5.8** | 73.0 ± 9.0 | 73.0 ± 13.2 | 101.4 ± 4.8 | 91.6 ± 7.8 | 127.0 ± 10.4**
Female
Urine (mg/dL) | 53.4 ± 5.1** | 49.4 ± 2.5 | 47.2 ± 7.8 | 66.4 ± 1.9 | 57.8 ± 3.8 | 100.6 ± 11.4**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BD = below detection; group did not have over 20% of its values above the limit of detection (LOD).

^a^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^b^ Data are presented as mean ± standard error.

^c^ Concentrations in drinking water refer to freebase (-)-nicotine.

^d^ If over 20% of the values for nicotine or cotinine in the plasma or urine of animals in a group were above the LOD, one-half the LOD value was substituted for values below the LOD. All values for creatinine in urine below the LOD were substituted with one-half the LOD.

^e^ If 80% or more of the values in the vehicle control group were below the LOD, no mean and standard error were calculated and no statistical analysis was performed.

Table 33 Summary of Internal Concentration Data for Male and Female Mice in the Three-month Drinking Water Study of Nicotine Bitartrate Dihydrate^a,b,c^

| 0 mg/L | 6.25 mg/L | 12.5 mg/L | 25 mg/L | 50 mg/L | 100 mg/L
n | 5 | 5 | 5 | 5 | 5 | 5
Nicotine Concentration^d^
Male
Plasma (ng/mL) | 1.44 ± 0.772** | 7.35 ± 2.99 | 18.7 ± 9.40* | 27.1 ± 7.07** | 56.7 ± 6.04** | 183 ± 38.7**
Urine (ng/mL) | 5.05 ± 0.747** | 42.9 ± 9.68*^e^ | 129 ± 15.4**^e^ | 193 ± 69.9** | 656 ± 153** | 1,360 ± 681**
Creatinine-adjusted urine (ng/mg) | 37.1 ± 8.1** | 286.3 ± 80.8* | 1,360.0 ± 399.6** | 1,593.6 ± 659.0** | 2,784.5 ± 785.4** | 4,448.7 ± 1,296.2**
Female
Plasma (ng/mL) | BD^f^ | 3.87 ± 1.25 | 5.33 ± 1.10 | 18.6 ± 5.48 | 33.7 ± 12.1 | 142 ± 51.8
Urine (ng/mL) | 6.43 ± 1.48** | 40.3 ± 7.85* | 55.5 ± 16.3** | 120 ± 29.6** | 237 ± 47.9** | 616 ± 141**
Creatinine-adjusted urine (ng/mg) | 66.0 ± 18.9** | 498.6 ± 204.7* | 435.0 ± 256.8* | 956.7 ± 355.2** | 1,430.2 ± 336.3** | 3,530.5 ± 1,519.0**
Cotinine Concentration^d^
Male
Plasma (ng/mL) | 1.14 ± 0.352** | 22.7 ± 4.25** | 178 ± 90.3** | 185 ± 23.2** | 343 ± 64.8** | 857 ± 111**
Urine (ng/mL) | 0.663 ± 0.058** | 105 ± 22.0** | 718 ± 166** | 546 ± 196** | 1,490 ± 147** | 4,940 ± 2,290**
Creatinine-adjusted urine (ng/mg) | 4.9 ± 1.0** | 818.9 ± 384.2** | 9,323.2 ± 3,258.6** | 5,238.9 ± 2,372.8** | 6,625.6 ± 1,548.4** | 16,486.8 ± 4,457.9**
Female
Plasma (ng/mL) | BD^f^ | 21.2 ± 6.09 | 41.0 ± 11.3 | 112 ± 25.6 | 198 ± 44.6 | 1,030 ± 146
Urine (ng/mL) | 0.701 ± 0.116**^e^ | 146 ± 63.1* | 337 ± 90.4** | 529 ± 88.3** | 1,250 ± 261** | 2,850 ± 285**
Creatinine-adjusted urine (ng/mg) | 6.6 ± 1.2** | 3,108.3 ± 2,469.3* | 2,532.1 ± 1,330.8** | 3,558.4 ± 839.6** | 6,821.6 ± 864.0** | 14,785.9 ± 5,888.5**
Creatinine Concentration^d^
Male
Urine (mg/dL) | 15.6 ± 2.8 | 18.4 ± 3.5 | 13.2 ± 5.7 | 14.2 ± 3.6 | 27.8 ± 6.6 | 27.4 ± 6.8
Female
Urine (mg/dL) | 11.2 ± 2.1** | 11.6 ± 2.2 | 20.8 ± 4.4 | 16.8 ± 4.0 | 18.2 ± 3.7 | 27.4 ± 6.4*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BD = below detection; group did not have over 20% of its values above the limit of detection (LOD).

^a^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^b^ Data are presented as mean ± standard error.

^c^ Concentrations in drinking water refer to freebase (-)-nicotine.

^d^ If over 20% of the values for nicotine or cotinine in the plasma or urine of animals in a group were above the LOD, one-half the LOD value was substituted for values below the LOD. All values for creatinine in urine below the LOD were substituted with one-half the LOD.

^e^ Two urine nicotine observations from 6.25 and 12.5 mg/L males and one urine cotinine observation from a control female were excluded from analysis as outliers.

^f^ If 80% or more of the values in the vehicle control group were below the LOD, no mean and standard error were calculated and no statistical analysis was performed.

In addition to nicotine and cotinine concentrations in plasma and urine samples, a qualitative assessment was performed to determine the presence of the metabolites and concentration estimates. Metabolites were present in varying concentrations in both plasma and urine. The summaries of these results are presented in Table C-3. Biological sample analysis graphs of nicotine and cotinine are also presented in Appendix C.