# Materials and Methods

## Toxicokinetic Studies for Test Article Selection

Limited toxicokinetic studies of freebase (-)-nicotine and nicotine bitartrate dihydrate (NBD) were performed using a single gavage administration to male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats, and systemic nicotine exposure was assessed to aid in test article selection. The in-life portion of the toxicokinetic studies was conducted at Battelle (West Jefferson, OH). Bulk chemical analysis, formulation preparation and analysis, and biological sample analyses were performed at Battelle (Columbus, OH). Rats received a single gavage administration of freebase (-)-nicotine or NBD in ASTM Type I water at a dose of 0.5 mg/kg. Because the tartrate salt crystallizes as the dihydrate, a monoisotopic mass of 498.2 g/mol was used for calculating freebase (-)-nicotine concentrations. Freebase (-)-nicotine represents 32.56% of the monoisotopic mass of the NBD compound. Additional information on the toxicokinetic studies is provided in Appendix B.

### Procurement and Characterization of Freebase (-)-Nicotine

Nicotine as freebase (-)-nicotine was obtained in a single lot (1515L008) from Siegfried (Zofingen, Switzerland) via Interchem Corporation (Paramus, NJ). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH) (Appendix A). Reports on analyses performed in support of these studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Freebase (-)-nicotine (lot 1515L008), a colorless to yellow or brownish liquid, was identified using infrared (IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, ^13^C NMR spectroscopy, and high-performance liquid chromatography (HPLC) with mass spectrometry (MS). The IR spectrum was consistent with a reference spectrum, the NMR spectra were consistent with the predicted spectra of freebase (-)-nicotine, and the HPLC/MS spectra and fragmentation were consistent with nicotine. Elemental analysis was also performed by Galbraith Laboratories (Knoxville, TN) to confirm the composition.

Purity was determined using HPLC with ultraviolet (UV) detection, differential scanning calorimetry (DSC), thermogravimetric analysis (TGA), and gas chromatography with flame ionization detection (GC/FID). Moisture content was measured by Karl Fischer titration performed by Galbraith Laboratories, and the specific rotation and water analyses were performed at Exova Inc. (Santa Fe Springs, CA).

Karl Fisher titration yielded a water content of 0.18%. The specific rotation analysis indicated an average of −133.2°C, and the water analysis indicated 0.23% water content (Appendix A). DSC measured the boiling point as 244.9°C. One impurity, likely ethanol, identified in the ^1^H NMR spectrum and quantified using GC/FID, was approximately 0.3% of the total area. Purity evaluation by HPLC/UV detection identified two impurity peaks representing 0.4% of the total area detected. The overall purity of lot 1515L0008 was determined to be >99% (Table 1).

Table 1 Summary of Chemical Purity in the Toxicokinetic Study of Freebase (-)-Nicotine

Lot Number | Water (%) | | Purity
Lot Number | KF | SRA | % Overall | Number of Detected Impurities | % Impurity
1515L008 | 0.18 | 0.23 | >99 | 2 | 0.4

KF = Karl Fisher titration; SRA = specific rotation analysis.

Accelerated stability studies were conducted on the bulk chemical using HPLC/UV to measure purity after storage at approximately −20°C, 5°C, room temperature, and 60°C while protected from light. Stability was maintained for at least 2 weeks at or below room temperature; therefore, the bulk test article was stored at 1°C–8°C and protected from light.

### Procurement and Characterization of Nicotine Bitartrate Dihydrate

NBD was obtained in a single lot (1531H012) from Siegfried (Zofingen, Switzerland) via Interchem Corporation (Paramus, NJ). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH) (Appendix A). Reports on analyses performed in support of the NBD studies are on file at NIEHS.

The chemical identity of NBD (lot 1531H012), a white or almost-white powder, was confirmed using IR spectroscopy, ^1^H NMR spectroscopy, ^13^C NMR spectroscopy, and HPLC/MS. The IR spectrum agreed with the structure of NBD, and NMR spectra were consistent with the predicted spectra of NBD. The HPLC/MS spectra and fragmentation were consistent with nicotine. Elemental analysis was also performed by Galbraith Laboratories (Knoxville, TN) to confirm the composition of NBD.

Purity was determined using HPLC with UV detection, DSC, and TGA. Moisture content was measured for the lot by Karl Fischer titration performed by Galbraith Laboratories, and the specific rotation and water analyses were performed at Exova Inc. (Santa Fe Springs, CA).

Karl Fisher titration yielded a water content of 8.97%. The specific rotation analysis indicated an average of +23.0°C, and the water analysis indicated 7.2% water content (Appendix A). DSC was attempted, but the nature of NBD (a dihydrate salt complex) resulted in broad duplicate overlapping peaks, and accurate purity and melting points could not be determined. No impurities were detected using HPLC/UV or TGA (Table 2).

Table 2 Summary of Chemical Purity in the Toxicokinetic, Four-week, and Three-month Studies of Nicotine Bitartrate Dihydrate

Lot Number | Water (%) | | Purity
Lot Number | KF | SRA | % Overall | Number of Detected Impurities | % Impurity
1531H012 | 8.97 | 7.2 | 100 | 0 | <0.1

KF = Karl Fisher titration; SRA = specific rotation analysis.

Accelerated stability studies were conducted on the bulk chemical using HPLC/UV to measure purity after storage at approximately −20°C, 5°C, room temperature, and 60°C while protected from light. Stability of NBD was maintained when sealed, protected from light, and stored for 2 weeks at ≤60°C. Thus, the bulk test article was stored at room temperature and protected from light.

## Preparation and Analysis of Drinking Water Formulations for the Palatability, Four-week, and Three-month Studies

Dose formulations for the 14-day (palatability) and 4-week studies were prepared at the Ramazzini Institute (Bologna, Italy) similarly to those for the 3-month studies but were not analyzed. The drinking water formulations for the 3-month studies were prepared weekly at the Ramazzini Institute (Bologna, Italy) by mixing NBD with tap water to give the desired concentrations for each species. All concentrations are given in mg nicotine/liter (mg/L). For the rat study, formulations were prepared at concentrations of 0, 1.56, 3.12, 6.25, 12.5, and 25 mg/L. For the mouse study, formulations were prepared at concentrations of 0, 6.25, 12.5, 25, 50, and 100 mg/L. Drinking water formulations were stored at room temperature in high-density polyethylene (HDPE) plastic bottles covered with black plastic foil to avoid light exposure and dispensed in dark glass bottles daily to the animals. Aliquots (from three different time points) of each preadministration formulation dose were frozen and sent in an insulated container to Battelle (Columbus, OH) for analysis, where they were stored at −30°C to −15°C until analyzed.

Select NBD formulations from the perinatal and 3-month rat study and the 3-month mouse study were analyzed by liquid chromatography with tandem mass spectrometry (LC-MS/MS) using a qualified method. The results of preadministration formulation analyses for the 3-month studies are shown in Table A-6 (rats) and Table A-7 (mice). No postadministration samples were analyzed. The concentrations of the NBD formulations analyzed prior to exposure were within 10% of the target concentrations, except for the 1.56 mg/L formulations from the perinatal and 3-month rat study received on April 27, 2017, and May 25, 2017, which were 59.0% and 15.7% above target, respectively. All rat formulations had relative standard deviation (RSD) values within 5%, except for the 6.25 mg/L formulation from the first shipment, which had an RSD value of 6.6%.

Multiple formulations had results outside the acceptance criteria for accuracy and precision (average concentration within 10% of the target concentration and RSD values within 5%). Several mouse formulations used in the study had RSD values outside 5% (ranging from 6.2% to 9.2%). These deviations were not considered to significantly affect the studies.

## Animal Source and Welfare

Male and female Sprague Dawley rats and Swiss mice were obtained from the Cesare Maltoni Cancer Research Center colony (Bologna, Italy). Sprague Dawley rats and Swiss mice were selected for these studies based on familiarity and historical information by the study laboratory, and the authors consider them to be good models for general toxicology evaluations including a perinatal design. Animal care and use were in accordance with the Italian law regulating the use and humane treatment of animals for scientific purposes (Decreto Legislativo N. 26, 2014, which adopts European Union Directive 2010/63/EU). Study protocols were examined, approved, and formally authorized by the Italian Ministry of Health.

## Palatability Study and Exposure Concentration Selection Rationale

For the palatability study in male and female Sprague Dawley rats and Swiss mice, selection of 0, 6.25, 12.5, 25, 50, or 100 mg/L exposure concentrations (as NBD) for up to 14 days was informed by literature on the range of nicotine and cotinine concentrations in serum of heavy smokers or electronic cigarette users. Smoking one cigarette per day yields about 1 mg of absorbed nicotine; therefore, a 70 kg person would take in 0.0143 mg nicotine/kg/day.^36^ Using five exposure concentrations and threefold spacing, the concentrations selected were 0.0143, 0.0429, 0.143, 0.429, and 1.287 mg freebase (-)-nicotine/kg (equivalent to 1, 3, 10, 30, and 90 cigarettes) based on a 70 kg person.

The palatability study provided preliminary information for the subsequent 4-week study in Sprague Dawley rats and Swiss mice exposed to NBD in drinking water. There were no exposure-related deaths or gross or microscopic findings in male or female rats in the palatability study at exposure concentrations of 6.25, 12.5, 25, or 50 mg/L. The highest exposure concentration of 100 mg/L was unpalatable for rats. In addition, exposure to 50 mg/L induced a significant reduction in final mean body weight and an approximately 50% reduction in final mean water consumption; therefore, it was not considered palatable. All other exposure concentrations (6.25, 12.5, and 25 mg/L) were considered palatable for rats. Therefore, the exposure concentrations selected for the perinatal and 4-week study in rats were 0, 1.56, 3.12, 6.25, 12.5, and 25 mg/L. All exposure concentrations (0, 6.25, 12.5, 25, 50, and 100 mg/L) were considered palatable for mice. Exposure concentrations of NBD equivalent to 0, 6.25, 12.5, 25, 50, and 100 mg/L of drinking water were selected for the 4-week study in mice.

## Four-week Dose Range-finding Studies

F_0_ female Sprague Dawley rats were 17 weeks old when the experiment started. They were mated and quarantined for 7 days and were approximately 20 weeks old on the first day of exposure. Gestation day (GD) 0 was defined as the first day with evidence of mating. Siblings were allocated to separate groups, and groups were normalized to attain similar group average body weights before mating. Randomization was performed using a random number generator. Beginning on GD 6, groups of five F_0_ female rats were provided NBD in drinking water throughout gestation and lactation at the following concentrations: 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/L; tap water served as the control. Due to high pup mortality observed during lactation, administration of NBD was interrupted, and all animals were given tap water instead of NBD in drinking water from approximately 4 days before weaning until the start of the 4-week study. Lactation day (LD) 21 was the last lactation day all animals were exposed. Feed and dosed water were available ad libitum.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. The day of parturition was considered LD 0 for dams and postnatal day (PND) 0 for pups. F_0_ female rats were weighed on GDs 5, 7–12, 15, 18, and 21 and LDs 1, 4, 7, 14, and 21. Feed and water consumption were also measured on these days. Pup body weights by sex and litter were recorded on PNDs 4, 7, 14, and 21.

Due to increased litter mortality, pups were weaned between PND 26 and PND 29 starting on PND 26 of the last litter that was born. Weaning marked the beginning of the 4-week study. Beginning on the day the last rat litter reached PND 30, the F_1_ rats were provided NBD in drinking water for 4 weeks at the following concentrations: 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/L; tap water served as the control. The control and high exposure groups (0 and 25 mg/L, respectively) consisted of 20 male and 20 female rats each. All other exposed groups (1.56, 3.12, 6.25, and 12.5 mg/L) consisted of 10 male and 10 female rats each. Pups were provided the same concentrations of NBD in drinking water as were provided to their respective dams during gestation. Dams were euthanized according to Ramazzini Institute protocols. Necropsy was not performed on F_0_ dams. Feed and dosed water were available ad libitum. F_1_ rats were housed two to three animals/sex/cage. Cages were periodically rotated. Details of the study design and animal maintenance are summarized in Table 3.

Table 3 Experimental Design and Materials and Methods in the Four-week and Three-month Drinking Water Studies of Nicotine Bitartrate Dihydrate

Four-week Studies | Three-month Studies
Study Laboratory
Cesare Maltoni Cancer Research Center, Ramazzini Institute (Bologna, Italy) | Same as in 4-week studies
Strain and Species
Rats: Sprague Dawley | Same as in 4-week studies
Mice: Swiss | Same as in 4-week studies
Animal Source
Cesare Maltoni Cancer Research Center (Bologna, Italy) | Same as in 4-week studies
Time Held Before Studies
F_0_ female rats: 7 days | Same as in 4-week studies
Mice: 7 days | Same as in 4-week studies
Average Age When Exposure Began
F_0_ female rats: 20 weeks | Same as in 4-week studies
Mice: 11 weeks | Same as in 4-week studies
Date of First Exposure
F_0_ female rats: October 31, 2016 | F_0_ female rats: April 25, 2017
Mice: October 31, 2016 | Mice: February 21, 2017
Duration of Exposure
F_0_ female rats: GD 6 through LD 21 (halted ~4 days prior to weaning due to high pup mortality) | F_0_ female rats: GD 6 through LD 28
F_1_ rats: Perinatal plus 4 weeks | F_1_ rats: Perinatal plus 13 weeks
Mice: 4 weeks | Mice: 13 weeks
Date of Last Exposure
F_0_ female rats: January 18, 2017 | F_0_ female rats: September 14, 2017
Mice: November 29, 2016 | Mice: May 24, 2017
Necropsy Dates
F_1_ rats: January 16–19, 2017 | F_1_ rats: September 11–15, 2017
F_1_ rats (recovery): January 30–31, 2017 | F_1_ rats: September 11–15, 2017
Mice: November 29–30, 2016 | Mice: May 22–25, 2017
Mice (recovery): December 12, 2016 | Mice: May 22–25, 2017
Average Age at Necropsy
F_1_ rats: 8 weeks | F_1_ rats: 17 weeks
Mice: 15 weeks | Mice: 24 weeks
Size of Study Groups
F_0_ female rats: 5 | F_0_ female rats: 8
F_1_ rats: 10/sex for the 4-week exposure (0, 1.56, 3.12, 6.25, 12.5, or 25 mg/L) plus 10/sex for the 4-week exposure with 2-week recovery period (0 and 25 mg/L) | F_1_ rats: 10/sex
Mice: 10/sex for the 4-week exposure (0, 6.25, 12.5, 25, 50, or 100 mg/L) plus 10/sex for the 4-week exposure with 2-week recovery period (0 and 100 mg/L) | Mice: 30/sex (0 and 100 mg/L); 15/sex (6.25, 12.5, 25, 50 mg/L)
Animals per Cage
F_1_ rats: 2 to 3/sex | Same as in 4-week studies
Mice: Up to 5/sex | Same as in 4-week studies
Method of Animal Identification
F_0_ female rats: Cage card | Same as in 4-week studies
F_1_ rats: Cage card and ear punch | Same as in 4-week studies
Mice: Cage card and ear punch | Same as in 4-week studies
Diet
Pelleted feed (Laboratorio Dottori Piccioni Srl, Gessate, Milan, Italy), available ad libitum, changed every 2–3 days | Same as in 4-week studies
Water
Tap water (Bologna municipal supply), either untreated or containing a formulation of nicotine bitartrate dihydrate via dark glass bottles, available ad libitum, changed daily | Same as in 4-week studies
Cages
During exposure: polycarbonate cages (41 × 25 × 18 cm) with stainless-steel wire tops, rotated periodically After exposure: polycarbonate and polymethylpentene metabolic cages (Techniplast, Buguggiate, Italy) | Same as in 4-week studies
Bedding
Shallow layer of white wood shavings, changed every 2–3 days | Same as in 4-week studies
Animal Room Environment
Temperature: 22°C ± 3°C Relative humidity: 50% ± 20% Natural and artificial light: 12 hours/day Room air changes: 10/hour | Same as in 4-week studies
Exposure Concentrations
Rats: 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/L in drinking water available ad libitum; from approximately 4 days before weaning until the start of the 4-week study, animals in all exposure groups were given untreated tap water | Rats: 0, 1.56, 3.12, 6.25, 12.5 or 25 mg/L in drinking water available ad libitum; dams in all exposed groups received only 1.56 mg/L during lactation
Mice: 0, 6.25, 12.5, 25, 50, or 100 mg/L in drinking water available ad libitum | Mice: Same as in 4-week studies
Type and Frequency of Observation
F_0_ female rats: Observed three times daily, except Sundays and nonworking days when they were observed twice daily; daily feed and water consumption and body weights were measured on GDs 5, 7–12, 15, 18, and 21; LDs 1, 4, 7, 14, and 21. | F_0_ female rats: Observed three times daily, except Sundays and nonworking days when they were observed twice daily; daily feed and water consumption and body weight were measured on GDs 5, 7, 9, 12, 15, 18, and 21; LDs 1, 4, 7, 10, 14, 17, 21, 24, and at weaning.
F_1_ rats: Observed three times daily, except Sundays and nonworking days when they were observed twice daily; clinical observations were recorded initially and at least weekly thereafter until study termination; body weights were measured by sex and litter on PNDs 4, 7, 14, and 21; individual body weights were measured the first day after weaning, then weekly thereafter until study termination; daily feed and water consumption and body weights were measured per cage the first day after weaning and then weekly thereafter until study termination; water consumption in metabolic cages was measured at study termination. During the recovery period, rats in the control and 25 mg/L recovery groups were observed three times daily except Sundays and nonworking days when they were observed twice daily; clinical observations were recorded initially and weekly thereafter until study termination; individual daily feed and water consumption and body weights were measured on the first day of water administration and weekly thereafter until study termination. | F_1_ rats: Observed three times daily, except Sundays and nonworking days when they were observed twice daily; clinical observations were recorded initially and at least weekly thereafter until study termination; body weights were measured by sex and litter on PNDs 1, 4, 7, 10, 14, 17, 21, 24, and at weaning; individual body weights were measured the first day after weaning, then weekly thereafter until study termination; daily feed and water consumption and body weights were measured per cage the first day after weaning and then weekly thereafter until study termination; water consumption in metabolic cages was measured at study termination.
Mice: Observed three times daily, except Sundays and nonworking days when they were observed twice daily; clinical observations were recorded initially and at least weekly thereafter until study termination; daily feed and water consumption and body weights were measured on day 1, day 3, and then weekly until study termination. During the recovery period, mice in the control and 100 mg/L recovery groups were observed three times daily except Sundays and nonworking days when they were observed twice daily; clinical observations were recorded initially and weekly thereafter until study termination; individual daily feed and water consumption and body weights were measured on the first day of water administration and weekly thereafter until study termination. | Mice: Observed three times daily, except Sundays and nonworking days when they were observed twice daily; clinical observations were recorded initially and at least weekly thereafter until study termination; daily feed and water consumption and body weights were measured on day 0, day 1, and then weekly until study termination.
Method of Euthanasia
Exsanguination while under CO_2_/O_2_ anesthesia | Same as in 4-week studies
Necropsy
Necropsies were performed on all F_1_ rats and all mice. Organs weighed at study termination were adrenal gland, bladder, brain (with cerebellum and medulla/pons), heart, kidneys, liver, mediastinal lymph nodes, ovaries, prostate, seminal vesicle (with coagulating gland), spleen, testes and epididymides, thymus, and uterus (with cervix). | Same as in 4-week studies
Clinical Pathology
F_1_ rats: At the end of the study, blood and urine were collected from 10 male and 10 female rats per group for clinical chemistry, hematology, and urinalysis. Following the 2-week recovery period, blood was collected from 10 male and 10 female rats from only the control and high exposure groups for clinical chemistry, hematology, and urinalysis. | F_1_ rats: At the end of the study, blood and urine were collected from 10 male and 10 female rats per exposure group for clinical chemistry, hematology, and urinalysis.
Hematology: Erythrocyte count, mean corpuscular volume, hemoglobin, hematocrit, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, white blood cell count and differential, reticulocyte count, platelet count, red cell distribution width, platelet distribution width, mean platelet volume, and plateletcrit. | Hematology: Same as in 4-week studies
Clinical chemistry: Sodium, potassium, chloride, glucose, inorganic phosphates, calcium, globulins, total cholesterol, triglycerides, blood urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, gamma glutamyl transferase, alkaline phosphatase, and total bilirubin. | Clinical chemistry: Same as in 4-week studies
Urinalysis: Appearance, volume, specific gravity, pH, total protein, glucose, ketone bodies, urobilinogen, bilirubin, and occult blood. | Urinalysis: Appearance, volume, specific gravity, pH, total protein, glucose, ketone bodies, urobilinogen, bilirubin, occult blood, and creatinine.
Mice: At the end of the 4-week exposure, blood was collected for clinical chemistry and hematology from 5 male and 5 female mice randomly selected from each exposure group. Following the 2-week recovery period, blood was collected for clinical chemistry and hematology from 5 male and 5 female mice randomly selected from the control and high exposure groups. | Mice: At the end of the study, blood was collected for clinical chemistry and hematology from 10 male and 10 female mice randomly selected from each exposure group.
Hematology: Erythrocyte count, mean corpuscular volume, hemoglobin, hematocrit, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, white blood cell count and differential, reticulocyte count, platelet count, red cell distribution width, platelet distribution width, mean platelet volume, and plateletcrit. | Hematology: Same as in 4-week studies
Clinical chemistry: Sodium, potassium chloride, glucose, inorganic phosphates, calcium, globulins, total cholesterol, triglycerides, blood urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, gamma glutamyl transferase, alkaline phosphatase, and total bilirubin. | Clinical chemistry: Same as in 4-week studies
Urinalysis: None | Urinalysis: Creatinine
Histopathology
Complete histopathology was performed on control and high exposure group animals. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bladder, gallbladder (mice only), brain (with cerebellum and medulla/pons), cranium, esophagus, Harderian gland, heart, kidneys, large intestine (with the Peyer’s patches), liver (caudate and main), lungs, lymph nodes (mediastinal, mesenteric, subcutaneous), mammary gland (axillary and inguinal, right and left), ovaries, pancreas, parathyroid, pituitary gland, prostate, salivary gland, seminal vesicle (with coagulating gland), skeletal muscle of the leg (with sciatic nerve), skin and subcutaneous tissue, small intestine, spinal cord (cervical, thoracic, and lumbar), spleen, sternum (bone marrow), stomach (forestomach and glandular), testes and epididymides, thymus, thyroid gland, tongue, trachea, uterus (with cervix), and vagina. | Complete histopathology was performed on all animals. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bladder, brain (with cerebellum and medulla/pons), cranium, esophagus, Harderian gland, heart, kidneys, large intestine (with the Peyer’s patches), liver (caudate and main), lungs, lymph nodes (mediastinal, mesenteric, subcutaneous), mammary gland (axillary and inguinal, right and left), ovaries, pancreas, parathyroid, pituitary gland, prostate, salivary gland, seminal vesicle (with coagulating gland), skeletal muscle of the leg (with sciatic nerve), skin and subcutaneous tissue, small intestine, spinal cord (cervical, thoracic, and lumbar), spleen, sternum (bone marrow), stomach (forestomach and glandular), testes and epididymides, thymus, thyroid gland, tongue, trachea, uterus (with cervix), and vagina.
Internal Concentration Assessment
Not reported | F_1_ rats: Plasma and urine concentrations of nicotine and cotinine were measured in all animals (10/sex/group) at study termination, following a 16-hour period in metabolic cages during which animals had free access to feed and the assigned group drinking water formulations.
Not reported | Mice: Plasma and urine concentrations of nicotine and cotinine were measured in five randomly selected animals/sex/group at study termination, following a 16-hour period in metabolic cages during which animals had free access to feed and the assigned group drinking water formulations.

GD = gestation day; LD = lactation day; PND = postnatal day.

Swiss mice were 10 weeks old when the experiment started. They were quarantined for 7 days and were approximately 11 weeks old on the first day of exposure. Mice were provided NBD in drinking water for 4 weeks at the following concentrations: 0, 6.25, 12.5, 25, 50, or 100 mg/L; tap water served as the control. The control and high exposure groups (0 and 100 mg/L, respectively) consisted of 20 male and 20 female mice each. All other exposed groups (6.25, 12.5, 25, and 50 mg/L) consisted of 10 male and 10 female mice each. Feed and dosed water were available ad libitum. Mice were housed up to five/sex/cage. Cages were periodically rotated. Details of the study design and animal maintenance are summarized in Table 3.

During the 4-week studies, rats and mice were observed three times daily for signs of mortality or moribundity, except Sundays and nonworking days when they were observed twice daily. Clinical observations, body weights, and daily feed and water consumption were recorded initially, weekly thereafter, and at study termination. After the 4 weeks of exposure, 10 animals per sex in the control and high (25 mg/L for rats; 100 mg/L for mice) exposure groups were monitored without exposure for a 2-week recovery period.

At the end of the 4-week studies, animals were anesthetized with a carbon dioxide/oxygen mixture, blood was collected from the caudal vena cava of 10 rats/sex/group and 5 mice/sex/group for hematology and clinical chemistry, and the animals were then euthanized via exsanguination. Blood was collected into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_EDTA) for hematology and into tubes containing lithium heparin for clinical chemistry. Hematological parameters were measured using a Procyte Dx hematology analyzer (IDEXX), and clinical chemistry parameters were measured using a Catalyst DX clinical chemistry analyzer (IDEXX). Urine samples were collected from 10 rats/sex/group for standard urinalysis following approximately 16 hours in individual metabolic cages. Urine specific gravity was measured using a Euromax hand refractometer RF312. All other urine endpoints were measured with Combur10 test M urine test strips (Roche) and a Urisys 1800 semi-automated urinalysis system (Roche). The clinical pathology parameters measured are listed in Table 3.

Necropsies were performed on all F_1_ male and female rats and all mice. Organ weights were determined for the adrenal gland, bladder, brain (with cerebellum and medulla/pons), heart, kidneys, liver, mediastinal lymph nodes, ovaries, prostate, seminal vesicle (with coagulating gland), spleen, testes and epididymides, thymus, and uterus (with cervix) from all rats and mice. Tissues for microscopic examination were fixed and preserved in 70% alcohol, processed, trimmed, embedded in paraffin, sectioned to a thickness of 3–6 μm, and stained with hematoxylin and eosin (H&E). Complete histopathological examinations were performed by the study laboratory pathologist on 10 animals from the control male and female groups and 10 animals from the high exposure male and female groups. Table 3 lists the tissues and organs examined.

## Three-month Studies

### Study Design in Rats

F_0_ female Sprague Dawley rats were 17 weeks old when the experiment started. They were mated and quarantined for 7 days and were approximately 20 weeks old on the first day of exposure. GD 0 was defined as the first day with evidence of mating. Siblings were allocated to separate groups, and groups were normalized to attain similar group average body weights before mating. Randomization was performed using a random number generator. Beginning on GD 6, groups of eight F_0_ female rats were provided NBD in drinking water throughout gestation at the following concentrations: 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/L; tap water served as the control. Throughout lactation, all groups, apart from the control group, were provided NBD in drinking water at a concentration of 1.56 mg/L due to the unexpected pup mortality observed during lactation in the 4-week study at all higher exposure concentrations. Feed and dosed water were available ad libitum.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. F_0_ female rats were weighed on GDs 5, 7, 9, 12, 15, 18, and 21; LDs 1, 4, 7, 10, 14, 17, 21, and 24; and at weaning. Feed and water consumption were also measured on those days. The day of parturition was considered LD 0 for dams and PND 0 for pups. Pup body weights by sex and litter were recorded on PNDs 1, 4, 7, 10, 14, 17, 21, 24, and at weaning.

On the day the last litter reached PND 28, pups were weaned, and 10 animals/sex/group were randomly selected and housed 2 or 3/sex/cage. Weaning marked the beginning of the 3-month study. After weaning, groups of 10 male and 10 female F_1_ rats were provided NBD in drinking water for 3 months at the following concentrations: 0, 1.56, 3.12, 6.25, 12.5, or 25 mg/L; tap water served as the control. Pups were provided the same concentration of NBD in drinking water as their respective dams received during gestation. Dams were euthanized according to Ramazzini Institute protocols. Necropsy was not performed on dams. Feed and dosed water were available ad libitum. Cages were periodically rotated. Details of the study design and animal maintenance are summarized in Table 3.

### Study Design in Mice

Swiss mice were 11 weeks old when the experiment started. They were quarantined for 7 days and were approximately 11 weeks old on the first day of exposure. Mice were provided NBD in drinking water for 3 months at the following concentrations: 0, 6.25, 12.5, 25, 50, or 100 mg/L; tap water served as the control. The control and high exposure groups (0 and 100 mg/L, respectively) consisted of 30 male and 30 female mice each. Satellite groups of 15 male and 15 female mice in the control and high exposure groups were included for in-life observations. All other exposed groups (6.25, 12.5, 25, and 50 mg/L) consisted of 15 male and 15 female mice each. Feed and dosed water were available ad libitum. Mice were housed up to five/sex/cage. Cages were periodically rotated. Details of the study design and animal maintenance are summarized in Table 3.

### Clinical Examinations and Pathology

During the 3-month studies, rats and mice were observed three times daily for signs of mortality or moribundity, except Sundays and nonworking days when they were observed twice daily. Clinical observations, body weights, and daily feed and water consumption were recorded initially, weekly thereafter, and at study termination.

At the end of the 3-month studies, animals were anesthetized with a carbon dioxide/oxygen mixture, blood was collected from the caudal vena cava of 10 rats/sex/group and 5 mice/sex/group for hematology and clinical chemistry, and the animals were then euthanized via exsanguination. Blood was collected into tubes containing K_3_EDTA for hematology and into tubes containing lithium heparin for clinical chemistry. Hematology parameters were measured using a Procyte Dx hematology analyzer (IDEXX), and clinical chemistry parameters were measured using a Catalyst DX clinical chemistry analyzer (IDEXX). Urine samples were collected from 10 rats/sex/group for standard urinalysis. Urine specific gravity was measured using a Euromax hand refractometer RF312. All other urine endpoints were measured with Combur10 test M urine test strips (Roche) and a Urisys 1800 semi-automated urinalysis system (Roche). The clinical pathology parameters measured are listed in Table 3.

Necropsies were performed on all F_1_ male and female rats and all mice (excluding satellite groups). Organ weights were determined for the adrenal gland, bladder, brain (with cerebellum and medulla/pons), heart, kidneys, liver, mediastinal lymph nodes, ovaries, prostate, seminal vesicle (with coagulating gland), spleen, testes and epididymides, thymus, and uterus (with cervix) from all rats and mice. Tissues for microscopic examination were fixed and preserved in 70% alcohol, processed, trimmed, embedded in paraffin, sectioned to a thickness of 3 to 6 μm, and stained with H&E. Complete histopathological examinations were performed by the study laboratory pathologist on all animals. Table 3 lists the tissues and organs examined. Peer review of the pathology observations, conducted by the Division of Translational Toxicology (DTT) pathologists, focused on outcomes from the 3-month studies with select review of observations from the 4-week studies to confirm temporal consistencies.

### Internal Concentration Assessment

Following NBD exposure via drinking water for 3 months, plasma and urine samples were collected from rats and mice, stored at −70°C, and shipped to Battelle (Columbus, OH) for analysis of nicotine and cotinine concentrations. On PND 90, all animals (10 rats/sex/group, 30 mice per sex for the control and high exposure groups and 15 mice per sex for all other exposed groups) were placed individually in metabolic cages for approximately 16 hours. During this time, animals had free access to the drinking water formulations and feed. The following morning, urine and plasma samples were collected from 10 rats/sex/group and 5 randomly selected mice/sex/group. Animals were anesthetized by inhalation using a mixture of carbon dioxide and oxygen (70% and 30%, respectively), blood was collected from the cava vein into tubes containing K_3_EDTA, and the animals were then euthanized via exsanguination. The samples were gently inverted for 30 seconds to mix the contents and centrifuged at 1,500 rpm for 10 minutes at 4°C. Plasma was harvested (two aliquots, approximately 150 μL each) and stored at −70°C until analysis.

Plasma and urine study samples from rats and mice, calibration standards, blanks, and quality control samples were processed by a solid-phase extraction, eluting with 5% ammonium hydroxide in methanol, and analyzed by LC-MS/MS (Table 3; Appendix C). The urine samples were analyzed for creatinine. Additionally, the samples were screened for nicotine metabolites, including trans-3′-hydroxy cotinine, (S)-cotinine N-oxide, cotinine N-β-D-glucuronide, (R,S)-norcotinine, (R,S)-nornicotine, trans-3′-hydroxy cotinine O-β-D-glucuronide, (1′S,2′S)-nicotine 1′-oxide, and nicotine N-β-D-glucuronide.

## Statistical Methods

Statistical methods were chosen based on distributional assumptions as well as on the need to incorporate within-litter correlation among animals (for the perinatal rat studies). For F_1_ animal data during the lactation phase, data were summarized as a mean of litter means to appropriately account for within-litter correlation prior to performing statistical analysis. After weaning, data were summarized by individual animals. Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposed group against the control group. Significance of all trend and pairwise tests is determined by a p value of ≤0.05 and is reported at both 0.05 and 0.01 levels.

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as numbers of animals bearing such lesions at a specific anatomical site and the numbers of animals with that site examined microscopically. Fisher’s exact test,^37^ a procedure that uses the overall proportion of affected animals, was used to determine significance between exposed and control animals. In the perinatal and 3-month studies, the Cochran-Armitage linear trend test was used to test for significant trends for select lesion categories.^38^

### Analysis of Continuous Variables

Body weight, body weight gain, water and feed consumption, and clinical pathology data, including organ weight, hematology, and clinical chemistry, were statistically investigated through one-way analysis of variance (ANOVA) followed by the Dunnett test (when applicable).^39^

For the perinatal and 3-month studies in rats and mice, urine creatinine and internal concentration assessment data were analyzed using the nonparametric multiple comparison methods of Shirley^40^ (as modified by Williams^41^) and Dunn.^42^ The Jonckheere test^43^ was used to assess the significance of the exposure-related trends and to determine whether a trend-sensitive test (the Shirley test) would be more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure-related trend (the Dunn test). Before statistical analysis, outliers identified using the Dixon and Massey test^44^ were examined by NIEHS personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis. When individual concentration values were provided as “below the limit of detection” (LOD), one-half the LOD was used as a substitute value. However, if 80% or more of the values in the control group were below the LOD, the mean was reported as “BD” to indicate the values were “below detection” and no statistical analysis was performed on the endpoint.

## Quality Assurance Methods

An internal quality assurance unit at the Ramazzini Institute monitored scientific, operative, and structural requirements, including experimental conduct, data recording, analysis and storage of samples, personnel qualifications, and adequacy of all equipment used. A separate audit of the draft NIEHS Report was conducted for internal consistency and accuracy compared to supplemental data sources.