# Introduction

## Chemical and Physical Properties

Nicotine (CASRN 54-11-5) is a naturally occurring alkaloid and insecticide found in the solanaceous (nightshade) family of plants, which includes tobacco plants.^2^ In tobacco leaves, nicotine contributes approximately 95% of the total alkaloid content.^3^ While nicotine is a major component of cigarettes, it is also used therapeutically for smoking cessation. Nicotine in the tobacco plant exists mainly in the S-isomer form, with <1% of nicotine occurring as the R-isomer form. It is an oily, colorless to pale yellow liquid with a boiling point of 247°C and a molecular weight of 162.23 g/mol.^4^ It is soluble in water (log P 1.17) below 60°C and is soluble in organic solvents (e.g., alcohol, chloroform, oils).^2,5^ When exposed to light or air, nicotine gradually turns brown, and when heated to decomposition, it emits toxic fumes (e.g., nitrogen oxide, carbon monoxide).^6,7^ Nicotine, in its tartrate salt form as bitartrate dihydrate (Figure 1; CASRN 6019-06-3), is a hygroscopic, white powder. It has a melting point of 97°C–100°C and a molecular weight of 498.4 g/mol.^8,9^

Figure 1

Nicotine Bitartrate Dihydrate (CASRN 6019-06-3; Chemical Formula: C_10_H_14_N_2_•2C_4_H_6_O_6_•2H_2_O; Molecular Weight: 498.4 g/mol)

Synonyms: nicotine tartrate dihydrate; (S)-3-(1-methyl-2-pyrrolidinyl)pyridine (2R,3R)-2,3-dihydroxybutanedioate dihydrate.

## Production, Use, and Human Exposure

Nicotine is primarily isolated from the leaves of two species of tobacco plants in the nightshade plant family, Nicotiana tabacum and N. rustica.^2^ Human use of and exposure to nicotine generally comes from tobacco products, which contain different amounts of nicotine.^10^ People are exposed while processing and extracting tobacco (green tobacco sickness), storing and applying certain insecticides (now rare), and using any tobacco product.^11^ Nicotine constitutes one of the main compounds in tobacco products and electronic cigarettes and in chewing gums and other smoking cessation products.^12-14^ Almost 77% of adult smokers started smoking before 18 years of age, and every day in the United States, nearly 2,300 youth smoke their first cigarette.^15^ The global population of smokers is 1.1 billion, and approximately 80% live in low- and middle-income countries.^16^ A person smoking 25 cigarettes per day will absorb approximately 0.43 mg nicotine/kg body weight (mg/kg) and reach a nicotine blood concentration in the range of 4–72 ng/mL (0.025–0.444 μM).^17,18^

Concentrations of cotinine, the most abundant metabolite of nicotine in exposed mammals,^19^ in active smokers are generally >10 ng/mL in plasma and >200 ng/mL in urine.^20^ High concentrations of cotinine, comparable to the ones found in active smokers, have been found in the urine of electronic cigarette users.^21^

## Regulatory Status

Nicotine regulation is strongly connected with legislation affecting tobacco products and the emerging market for electronic cigarettes. In the United States, the U.S. Food and Drug Administration (FDA) has regulated cigarettes, smokeless tobacco, and roll-your-own tobacco since 2009 and recently finalized a rule to regulate all tobacco products, including electronic cigarettes, cigars, and hookah and pipe tobacco.^22^ On July 28, 2017, FDA announced a new comprehensive plan that places the issue of nicotine addiction at the center of the Agency’s tobacco regulation effort.^23^ In Europe, tobacco products are regulated by Directive 2014/40/EU.^24^

## Absorption, Distribution, Metabolism, and Excretion

The metabolism of nicotine is species specific. In humans, nicotine is extensively and rapidly metabolized by the liver to six primary metabolites and several minor metabolites. It is excreted, unchanged to a small degree (on average, approximately 5%), by the kidney. Quantitatively, the most abundant metabolite in mammalian species is cotinine; in humans, approximately 70%–80% of nicotine is converted to cotinine. Many mammalian species (e.g., mice, dogs, rabbits, monkeys) primarily metabolize nicotine to cotinine, as do humans, whereas rats and guinea pigs form as much nicotine-N′-oxide as cotinine and 3′-hydroxycotinine because of differences in the predominant cytochrome P450 enzymes.^19^ In all species, the liver provides considerable first-pass metabolism of nicotine before it enters systemic circulation from the gastrointestinal tract following oral or intraperitoneal exposure. Nicotine plasma half-life in rodents is generally shorter than in primates (45 minutes in rats and 6–7 minutes in mice versus 2 hours in humans and nonhuman primates).^19^ Therefore, absorption, distribution, metabolism, excretion and underlying kinetics are important processes to consider when designing animal experiments to achieve internal nicotine doses comparable to those expected in humans.^19^

## Pharmacology and Associated Toxicities

The primary pharmacological action of nicotine results when it binds to presynaptic nicotinic cholinergic receptors in the central and peripheral nervous system and neuromuscular junctions. Nicotine is readily taken up from circulation into the brain, where exposure activates the receptor and where persistent exposure can desensitize or competitively block interaction with acetylcholine, the natural ligand. Binding affects activity of corticobasal ganglia-thalamic brain circuits, initiating a secondary cascade of neurotransmitter release—including dopamine, norepinephrine, acetylcholine, serotonin, γ-aminobutyric acid (GABA), glutamate, and endorphins—in the prefrontal cortex, thalamus, and visual system, leading to a myriad of physiological and behavioral effects.^25^

Physiological and toxic responses to nicotine are complex and dependent on dose. In low doses, nicotine increases heart rate, blood pressure, respiratory rate, and alertness. As doses increase, symptoms include headache, dizziness, confusion, anxiety, and tremors and can lead to lethargy, convulsions, and coma. A variety of cardiac dysrhythmias have been reported, and severe intoxications can result in respiratory paralysis.^26^

Nicotine’s effects on the body also differ across lifespan. As reviewed in Ren et al.^27^ nicotine can cross the placental barrier, leading to in utero exposure. Nicotine exposure in utero can affect fetal hemodynamics, which can lead to tissue hypoxia, restrict intrauterine and postnatal growth, and increase the risks of fetal morbidity and mortality. Testosterone production is inhibited in males, and both sexes exhibit an increase in motor, sensory, cognitive, and behavioral deficits at infant and toddler stages. Studies in rodents have demonstrated specific effects of nicotine on brain development in areas controlling cardiac and respiratory functions at levels below those resulting in general growth inhibition, and smoking during pregnancy is thought to be a major cause of sudden infant death syndrome, possibly from nicotine exposure.^28,29^

Early exposure to nicotine results in increased reward responses to nicotine and other drugs of abuse in adolescence, along with learning and memory deficits and emotional dysregulation that can persist into adulthood. In contrast, the aging brain’s exposure to nicotine is largely considered neuroprotective, delaying onset of Alzheimer’s dementia and Parkinson’s disease, and positively affecting attention, learning, and memory, as well as improving mood and reducing stress.^27^ Linker et al.^30^ demonstrated that nicotine affects brain microglia, which are involved in brain remodeling, differently in adolescent and adult rats. Microglia activation after nicotine exposure in adolescence results in a proinflammatory state, which has been suggested to restructure synaptic pruning patterns in reward-encoding brain regions. Nicotine exposure suppresses reactive microglia in the adult brain, however.

Risks for chronic cardiovascular and respiratory diseases and cancers are elevated for smokers, but the specific contribution of nicotine to these well-recognized smoking sequelae is unclear.^27^ Data on the potential carcinogenicity of nicotine are sparse. Most nicotine studies in the AMES Salmonella assay (including urine of rats exposed to nicotine) were negative; however, nicotine induced DNA damage in the Escherichia coli pol A+/pol− test.^31^ There is inadequate evidence of an association between nicotine exposure and carcinogenic effects in human studies.^32^ In animal studies, Haussmann and Fariss concluded there was limited evidence suggesting an association between long-term nicotine exposure and a “lack of complete carcinogenic effects,”^32^ and the International Agency for Research on Cancer does not classify nicotine as a carcinogen.^33^ Tang et al.^34^ more recently reported that electronic cigarette smoke was carcinogenic in FVB/N mice, causing lung adenocarcinomas, but no rodent cancer bioassays of a traditional design have been reported.

## Study Rationale

Increasing human exposure to nicotine (in the absence of other tobacco smoke components) from electronic cigarettes and smoking cessation therapies prompted interest in more comprehensive rodent toxicology and cancer studies than was available in the existing literature. Nicotine bitartrate dihydrate (NBD) was selected as the test article because of its solubility, palatability, and use in nicotine-containing consumer products. Additionally, preliminary toxicokinetic information suggested that it results in systemic exposure similar to freebase (-)-nicotine. Lunell et al.^35^ showed that the primary site of nicotine absorption from a nicotine inhaler was the oral mucosa; therefore, drinking water was selected as the route of administration to model the episodic human exposure from smoking or vaping. To consider the potential for exposure to nicotine during pregnancy, a perinatal component was included in the rat study. While human exposure likely includes nicotine exposure prior to conception, this study focused on post-implantation outcomes.