# Acknowledgments

This work was supported by the Intramural Research Program (ES103376, ES103379, and ES103380) at the National Institute of Environmental Health Sciences (NIEHS), National Institutes of Health and performed for NIEHS under contracts HHSN273201600011C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201500006C, HHSN273201500014C, HHSN273201400015C, HHSN273201400027C, and HHSN316201200054W.