# Appendix D Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NIEHS-DATA-NIEHS-11.^45^

## D.1 Individual Animal Data - Rats

### D.1.1 Two-week Palatability Study in Rats

Nicotine_2WeekPalatability_Rats_FEMALE_Body_Weight.xlsx

Nicotine_2WeekPalatability_Rats_FEMALE_Feed_Consumption.xlsx

Nicotine_2WeekPalatability_Rats_FEMALE_Water_Consumption.xlsx

Nicotine_2WeekPalatability_Rats_FEMALE_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_2WeekPalatability_Rats_MALE_Body_Weight.xlsx

Nicotine_2WeekPalatability_Rats_MALE_Feed_Consumption.xlsx

Nicotine_2WeekPalatability_Rats_MALE_Water_Consumption.xlsx

### D.1.2 Perinatal and Four-week Dose Range-finding Study in Rats

Nicotine_4Week_Rats_DAM_PUP_Lactation_Feed_Consumption.xlsx

Nicotine_4Week_Rats_DAM_PUP_Lactation_Water_Consumption.xlsx

Nicotine_4Week_Rats_DAM_Gestation_Body_Weight.xlsx

Nicotine_4Week_Rats_DAM_Gestation_Feed_Consumption.xlsx

Nicotine_4Week_Rats_DAM_Gestation_Water_Consumption.xlsx

Nicotine_4Week_Rats_DAM_Lactation_Body_Weight.xlsx

Nicotine_4Week_Rats_FEMALE_Adult_Body_Weight.xlsx

Nicotine_4Week_Rats_FEMALE_Adult_Feed_Consumption.xlsx

Nicotine_4Week_Rats_FEMALE_Adult_Water_Consumption.xlsx

Nicotine_4Week_Rats_FEMALE_Adult_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_4Week_Rats_FEMALE_Clinical_Chemistry.xlsx

Nicotine_4Week_Rats_FEMALE_Clinical_Chemistry_Recovery.xlsx

Nicotine_4Week_Rats_FEMALE_Hematology.xlsx

Nicotine_4Week_Rats_FEMALE_Hematology_Recovery.xlsx

Nicotine_4Week_Rats_FEMALE_Nonneoplastic_Pathology.xlsx

Nicotine_4Week_Rats_FEMALE_Organ_Weight.xlsx

Nicotine_4Week_Rats_FEMALE_Organ_Weight_Recovery.xlsx

Nicotine_4Week_Rats_Litter_Mortality.xlsx

Nicotine_4Week_Rats_MALE_Adult_Body_Weight.xlsx

Nicotine_4Week_Rats_MALE_Adult_Feed_Consumption.xlsx

Nicotine_4Week_Rats_MALE_Adult_Water_Consumption.xlsx

Nicotine_4Week_Rats_MALE_Adult_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_4Week_Rats_MALE_Clinical_Chemistry.xlsx

Nicotine_4Week_Rats_MALE_Clinical_Chemistry_Recovery.xlsx

Nicotine_4Week_Rats_MALE_Hematology.xlsx

Nicotine_4Week_Rats_MALE_Hematology_Recovery.xlsx

Nicotine_4Week_Rats_MALE_Nonneoplastic_Pathology.xlsx

Nicotine_4Week_Rats_MALE_Organ_Weight.xlsx

Nicotine_4Week_Rats_MALE_Organ_Weight_Recovery.xlsx

Nicotine_4Week_Rats_PUP_Lactation_Body_Weight.xlsx

Nicotine_4Week_Rats_PUP_Postmortem_Pathology.xlsx

### D.1.3 Perinatal and Three-month Study in Rats

PA44_-_3Month_Rats_Urinalysis_Summary.pdf

PA48_-_3Month_Rats_Tissue_Concentration_Summary.pdf

Nicotine_3Month_Rats_DAM_PUP_Lactation_Feed_Consumption.xlsx

Nicotine_3Month_Rats_DAM_PUP_Lactation_Water_Consumption.xlsx

Nicotine_3Month_Rats_DAM_Gestation_Body_Weight.xlsx

Nicotine_3Month_Rats_DAM_Gestation_Feed_Consumption.xlsx

Nicotine_3Month_Rats_DAM_Gestation_Water_Consumption.xlsx

Nicotine_3Month_Rats_DAM_Lactation_Body_Weight.xlsx

Nicotine_3Month_Rats_FEMALE_Adult_Body_Weight.xlsx

Nicotine_3Month_Rats_FEMALE_Adult_Feed_Consumption.xlsx

Nicotine_3Month_Rats_FEMALE_Adult_Water_Consumption.xlsx

Nicotine_3Month_Rats_FEMALE_Adult_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_3Month_Rats_FEMALE_Clinical_Chemistry.xlsx

Nicotine_3Month_Rats_FEMALE_Hematology.xlsx

Nicotine_3Month_Rats_FEMALE_Neoplastic_Pathology.xlsx

Nicotine_3Month_Rats_FEMALE_Nonneoplastic_Pathology.xlsx

Nicotine_3Month_Rats_FEMALE_Organ_Weight.xlsx

Nicotine_3Month_Rats_MALE_Adult_Body_Weight.xlsx

Nicotine_3Month_Rats_MALE_Adult_Feed_Consumption.xlsx

Nicotine_3Month_Rats_MALE_Adult_Water_Consumption.xlsx

Nicotine_3Month_Rats_MALE_Adult_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_3Month_Rats_MALE_Clinical_Chemistry.xlsx

Nicotine_3Month_Rats_MALE_Hematology.xlsx

Nicotine_3Month_Rats_MALE_Nonneoplastic_Pathology.xlsx

Nicotine_3Month_Rats_MALE_Organ_Weight.xlsx

Nicotine_3Month_Rats_PUP_Lactation_Body_Weight.xlsx

Nicotine_3Month_Rats_Removal_Reasons.xlsx

## D.2 Individual Animal Data - Mice

### D.2.1 Two-week Palatability Study in Mice

Nicotine_2WeekPalatability_Mice_FEMALE_Body_Weight.xlsx

Nicotine_2WeekPalatability_Mice_FEMALE_Feed_Consumption.xlsx

Nicotine_2WeekPalatability_Mice_FEMALE_Water_Consumption.xlsx

Nicotine_2WeekPalatability_Mice_MALE_Body_Weight.xlsx

Nicotine_2WeekPalatability_Mice_MALE_Feed_Consumption.xlsx

Nicotine_2WeekPalatability_Mice_MALE_Water_Consumption.xlsx

### D.2.2 Four-week Dose Range-finding Study in Mice

Nicotine_4Week_Mice_FEMALE_Body_Weight.xlsx

Nicotine_4Week_Mice_FEMALE_Clinical_Chemistry.xlsx

Nicotine_4Week_Mice_FEMALE_Clinical_Chemistry_Recovery.xlsx

Nicotine_4Week_Mice_FEMALE_Feed_Consumption.xlsx

Nicotine_4Week_Mice_FEMALE_Hematology.xlsx

Nicotine_4Week_Mice_FEMALE_Hematology_Recovery.xlsx

Nicotine_4Week_Mice_FEMALE_Nonneoplastic_Pathology.xlsx

Nicotine_4Week_Mice_FEMALE_Organ_Weight.xlsx

Nicotine_4Week_Mice_FEMALE_Organ_Weight_Recovery.xlsx

Nicotine_4Week_Mice_FEMALE_Water_Consumption.xlsx

Nicotine_4Week_Mice_FEMALE_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_4Week_Mice_MALE_Body_Weight.xlsx

Nicotine_4Week_Mice_MALE_Clinical_Chemistry.xlsx

Nicotine_4Week_Mice_MALE_Clinical_Chemistry_Recovery.xlsx

Nicotine_4Week_Mice_MALE_Feed_Consumption.xlsx

Nicotine_4Week_Mice_MALE_Hematology.xlsx

Nicotine_4Week_Mice_MALE_Hematology_Recovery.xlsx

Nicotine_4Week_Mice_MALE_Nonneoplastic_Pathology.xlsx

Nicotine_4Week_Mice_MALE_Organ_Weight.xlsx

Nicotine_4Week_Mice_MALE_Organ_Weight_Recovery.xlsx

Nicotine_4Week_Mice_MALE_Water_Consumption.xlsx

Nicotine_4Week_Mice_MALE_Water_Consumption_Metabolic_Cage.xlsx

### D.2.3 Three-month Study in Mice

PA44_-_3Month_Mice_Urinalysis_Summary.pdf

PA48_-_3Month_Mice_Tissue_Concentration_Summary.pdf

Nicotine_3Month_Mice_FEMALE_Body_Weight.xlsx

Nicotine_3Month_Mice_FEMALE_Clinical_Chemistry.xlsx

Nicotine_3Month_Mice_FEMALE_Feed_Consumption.xlsx

Nicotine_3Month_Mice_FEMALE_Hematology.xlsx

Nicotine_3Month_Mice_FEMALE_Neoplastic_Pathology.xlsx

Nicotine_3Month_Mice_FEMALE_Nonneoplastic_Pathology.xlsx

Nicotine_3Month_Mice_FEMALE_Organ_Weight.xlsx

Nicotine_3Month_Mice_FEMALE_Water_Consumption.xlsx

Nicotine_3Month_Mice_FEMALE_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_3Month_Mice_MALE_Body_Weight.xlsx

Nicotine_3Month_Mice_MALE_Clinical_Chemistry.xlsx

Nicotine_3Month_Mice_MALE_Feed_Consumption.xlsx

Nicotine_3Month_Mice_MALE_Hematology.xlsx

Nicotine_3Month_Mice_MALE_Neoplastic_Pathology.xlsx

Nicotine_3Month_Mice_MALE_Nonneoplastic_Pathology.xlsx

Nicotine_3Month_Mice_MALE_Organ_Weight.xlsx

Nicotine_3Month_Mice_MALE_Water_Consumption.xlsx

Nicotine_3Month_Mice_MALE_Water_Consumption_Metabolic_Cage.xlsx

Nicotine_3Month_Mice_Removal_Reasons.xlsx