# Appendix C Nicotine Bitartrate Dihydrate Internal Concentration Assessment

## C.1 Sample Collection

### C.1.1 Urine

After nicotine bitartrate dihydrate (NBD) administration via drinking water for 3 months, urine samples were collected from rats and mice, stored at –70°C, and shipped to Battelle (Columbus, OH) for biological sample analysis and evaluation of nicotine, cotinine, and creatinine concentrations. At week 12 of the 3-month studies, rats and mice were removed from study cages and placed in individual metabolism cages for 16 hours. Drinking water formulations and feed were available ad libitum. Urine samples were collected the following morning from all rats (10/sex/group) and randomly selected mice (5/sex/group) for internal concentration assessment.

### C.1.2 Blood

At study termination, rats and mice were anesthetized with a carbon dioxide and oxygen mixture (70% and 30%, respectively), and blood was collected from all rats (10/sex/group) and randomly selected mice (5/sex/group) for internal concentration assessment. Blood was drawn from the cava vein into tubes containing potassium ethylenediaminetetraacetic acid (K_3_EDTA). The tubes were gently inverted for 30 seconds to mix the contents and centrifuged at 1,500 rpm for 10 minutes at 4°C. Plasma was harvested (two aliquots, approximately 150 μL each) and stored at −70°C until analysis.

## C.2 Sample Analysis

Nicotine and cotinine levels in samples from the 3-month studies were quantified using validated analytical methods, and method validation data are given in Table C-1 and Table C-2. Creatine was also quantified in rat and mouse urine. Qualitative measurements of metabolites trans-3’-hydroxy cotinine, (S)-cotinine N-oxide, cotinine N-β-D-glucuronide, (R,S)-norcotinine, (R,S)-nornicotine, trans-3’-hydroxy cotinine O-β-D-glucuronide, (1’S,2’S)-nicotine 1’-oxide, and nicotine N-β-D-glucuronide were also conducted on the rat and mouse plasma and urine (Table C-3).

Plasma and urine samples collected from male and female Sprague Dawley rats and male and female Swiss mice were received frozen on dry ice from the Ramazzini Institute (Bologna, Italy) and were stored at approximately –70°C when not being analyzed. The following matrix blanks used to prepare the calibration and quality control (QC) standards were received from BioIVT (Westbury, NY): male Sprague Dawley rat plasma (lot RAT329738) and male Swiss Webster mouse plasma (lot MSE263476) containing K_3_EDTA as an anticoagulant, male Sprague Dawley rat urine (lot RAT329735), and male Swiss Webster mouse urine (lot MSE263474). The following matrix blanks used to prepare the QC stability standards were received from the Ramazzini Institute (Bologna, Italy): male and female Sprague Dawley rat plasma and male and female Swiss mouse plasma containing K_3_EDTA as an anticoagulant, male and female Sprague Dawley rat plasma and urine, and male and female Swiss mouse urine.

Nicotine, cotinine, and the eight metabolites were measured using a calibration curve of seven matrix calibration standards ranging from 10 ng/mL to 200 ng/mL. Stock solutions for nicotine, cotinine, and each metabolite were combined and appropriately diluted to create a set of solvent standard spiking solutions in ASTM Type I water. On each day of extraction, the solvent standard spiking solutions were diluted 1/10 in the appropriate blank matrix from BioIVT (rat or mouse, plasma or urine) to create the final matrix calibration standards. Racemic nicotine-d3 and cotinine-d3 (Toronto Research Chemicals, Inc [Toronto, Ontario, Canada]) were used as internal standards (IS). The working internal standard (WIS) solution at 150 ng/mL was made by dissolving the respective source chemicals in methanol and then diluting in an aqueous solution of 10% trichloroacetic acid (TCA). Standard solutions were stored refrigerated (at 2°C–8°C) when not in use.

Matrix QC standards were prepared in both rat and mouse plasma and urine matrices provided by BioIVT. Two standard concentrations were prepared at 150 ng/mL (high) and 15 ng/mL (low) and stored in individual aliquots at −70°C until use with each extraction set of the corresponding matrix. Similarly, matrix QC stability standards were prepared in the blank matrices provided by the Ramazzini Institute (Bologna, Italy) and stored at −70°C in the same freezer as the study samples. The matrix QC stability standards’ results indicated there was no adverse effect on the samples during storage for nicotine and cotinine. The percentage difference between interrun-determined concentrations and expected concentrations are reported in Table C-2.

One hundred (100) µL of each matrix calibration standard, QC standard, blank, and study sample were transferred into individual microcentrifuge tubes. A 100 µL aliquot of the WIS was added to each tube, except for the blanks without IS. To the blanks without IS, 100 µL of 10% TCA in water was added. Each tube was mixed by vortex and centrifuged at maximum speed for approximately 5 minutes. Each well of a 96-well Oasis HLB solid-phase extraction plate (Waters, Milford, MA) was conditioned with 1 mL of methanol followed by 1 mL of 10% TCA in water. The wells were loaded with the supernatant of the pretreated sample. The samples were then eluted with 1 mL of 5% ammonium hydroxide in methanol into collection plates containing 100 µL of 1% hydrochloric acid. The eluent was evaporated to dryness under nitrogen at 40°C and then reconstituted with 100 µL of 10:90 methanol:10 mM ammonium bicarbonate in water. The samples were analyzed by liquid chromatography with tandem mass spectrometry (LC-MS/MS).

Creatinine concentrations in urine were measured directly with a Roche (Basel, Switzerland) cobas^®^ 6000 chemistry analyzer with the c501 module. Nicotine, cotinine, and creatinine concentrations in the study samples are listed in Table 32 and Table 33.

## C.3 Instrumentation and Quantitation

Samples from the 3-month studies were analyzed using LC-MS/MS (Table C-1, System F) in positive ionization mode. The system was considered suitable for a given run if at least three consecutive injections of a 30 ng/mL standard in the appropriate matrix had a relative standard deviation (RSD) of ≤10% using area ratios. Drift was considered acceptable if the average area ratio of duplicate injections of the standard was within 15% of the prerun system suitability average area ratio. The performance of the calibration curve was evaluated before the analysis of each sample set. A successful calibration was indicated by the following: correlation coefficient (r) ≥0.98; RSD ≤±10.0% (except at the lower limit of quantitation [LLOQ], where RSD was ≤±20%); relative error (RE) ≤±15.0% (except at LLOQ, where RE was ≤±20%) (Table C-2).

Calibration curves relating response ratio of analyte to internal standard (after correction for the background levels for the 3-month studies only) and concentration of nicotine and cotinine were constructed using a 1/X weighted linear regression. The analyte concentration in samples was calculated using response ratio, the regression equation, initial sample weight or volume, digestion volume, and dilution, when applicable. The concentration was reported as ng nicotine or cotinine/mL for plasma and urine and mg creatinine/dL for urine.

Data from study samples were considered valid if the system was deemed suitable and if QC standards passed two criteria: at least 67% of QC standards’ concentrations were within 15% of its nominal value and at least 50% of the QC standards’ RE was ≤15% at each target concentration level (low and high). All QC sets for each study sample set met these criteria.

Table C-1 Liquid Chromatography Systems Used for Internal Concentration Assessment Analysis in the Three-month Studies of Nicotine Bitartrate Dihydrate

Chromatography | Detection System | Column | Mobile Phase
System F
High-performance liquid chromatography | Tandem mass spectrometry, positive ion | Phenomenex Gemini NX-C18, (50 × 2 mm ID, 3 μm particle size) | A: 20 mM ammonium bicarbonate (aq) B: Acetonitrile Gradient program: A:B 90:10 to 25:75 in 3 minutes; 25:75 to 90:10 in 0.1 minute; hold at 90:10 for 1.9 minutes 500 µL/min flow rate

ID = internal diameter.

Table C-2 Analytical Method Qualification and Stability Data for Nicotine Bitartrate Dihydrate and Cotinine in Plasma and Urine for the Three-month Studies

Validation Parameter | Rat Plasma | Rat Urine | Mouse Plasma | Mouse Urine
Matrix Concentration Range (ng/mL)
LOQ (ng/mL)
Nicotine | 10.0 | 10.0 | 10.0 | 10.0
Cotinine | 9.96 | 9.96 | 9.96 | 9.96
LOD (ng/mL)
Nicotine | 0.360 | 2.54 | 2.93 | 3.21
Cotinine | 1.17 | 1.02 | 1.11 | 0.597
Correlation Coefficient (R^2^)
Nicotine | ≥0.9973 | ≥0.9974 | ≥0.9992 | ≥0.9903
Cotinine | ≥0.9892 | ≥0.9994 | ≥0.9987 | ≥0.9967
Precision and Accuracy
Nicotine intraday % RSD | ≤8.1 | ≤37.3 | ≤28.6 | ≤8.9
Nicotine intraday % RE | ≤±5.3 | ≤39.3 | ≤22.7 | ≤±5.3
Nicotine interday % RSD | NA^a^ | ≤26.3 | ≤24.1 | ≤7.0
Nicotine interday % RE | NA^a^ | ≤20.0 | ≤10.7 | ≤2.0
Cotinine intraday % RSD | ≤13.7 | ≤6.2 | ≤61.0 | ≤7.4
Cotinine intraday % RE | ≤±16.8 | ≤4.0 | ≤61.7 | ≤±2.7
Cotinine interday % RSD | ≤12.9 | ≤4.0 | ≤56.7 | ≤4.7
Cotinine interday % RE | ≤±8.1 | ≤2.7 | ≤30.2 | ≤±1.3
QC Stability % RE^b^
Nicotine | ≤7.3 | ≤4.0 | ≤6.0 | ≤16.7
Cotinine | ≤8.1 | ≤0.7 | ≤4.1 | ≤1.3

LOQ = limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error; NA = not applicable; QC = quality control.

^a^ QC samples were run on 1 day so there are no data to generate an interday value.

^b^ Estimated by comparing response of matrix standards to solvent standards.

## C.4 Results

Table C-3 Summary of Qualitative Assessment of Additional Metabolites in Rat and Mouse Plasma and Urine for the Perinatal and Three-month Study

Metabolite | Presence in Plasma^a^ | | Presence in Urine^a^
Metabolite | Rat | Mouse | Rat | Mouse
trans-3’-Hydroxy cotinine | NP | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups
(S)-Cotinine N-oxide | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups
Cotinine N-β-D-glucuronide | Present across all exposed groups | Present across all exposed groups | NR because a matrix peak interfered with the analyte, prohibiting quantitation | NR because a matrix peak interfered with the analyte, prohibiting quantitation
(R,S)-Norcotinine | Present in trace amounts in 1.56–12.5 mg/L groups, present in 25 mg/L group | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups
(R,S)-Nornicotine | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups
trans-3’-Hydroxy cotinine O-β-D-glucuronide | NP in 1.56 mg/L group, present in only a few samples in the 3.12–25 mg/L groups | Present in one sample in the 6.25 mg/L group, present in the remaining exposed groups | NP | Poor chromatography, unable to evaluate
(1’S,2’S)-Nicotine 1’-oxide | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups | Present across all exposed groups
Nicotine N-β-D-glucuronide | NP except trace amounts in the 25 mg/L group | NP or present in trace amounts in 6.25–25 mg/L groups, present in 50 and 100 mg/L groups | NR because a matrix peak interfered with the analyte, prohibiting quantitation | NR because a matrix peak interfered with the analyte, prohibiting quantitation

NP = not present; NR = not reportable.

^a^ Results from the control groups are not reported.

Figure C-1

Nicotine Plasma Concentrations in Male and Female Rats in the Perinatal and Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-2

Cotinine Plasma Concentrations in Male and Female Rats in the Perinatal and Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-3

Nicotine Plasma Concentrations in Male and Female Mice in the Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-4

Cotinine Plasma Concentrations in Male and Female Mice in the Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-5

Nicotine Urine Concentrations (Creatinine-adjusted) in Male and Female Rats in the Perinatal and Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-6

Cotinine Urine Concentrations (Creatinine-adjusted) in Male and Female Rats in the Perinatal and Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-7

Nicotine Urine Concentrations (Creatinine-adjusted) in Male and Female Mice in the Three-month Study of Nicotine Bitartrate Dihydrate

Figure C-8

Cotinine Urine Concentrations (Creatinine-adjusted) in Male and Female Mice in the Three-month Study of Nicotine Bitartrate Dihydrate