# Appendix B Toxicokinetic Studies in Rats

## B.1 Formulation Preparation and Analysis

Dose formulations for the toxicokinetic studies were prepared once at Battelle (Columbus, OH) by mixing freebase (-)-nicotine or nicotine bitartrate dihydrate (NBD) in ASTM Type I water at a concentration of 0.1 mg/mL. The freebase (-)-nicotine formulations were stored at 2°C–8°C, and the NBD formulations were stored at room temperature (Table A-3). Formulations were analyzed prior to dosing by liquid chromatography with tandem mass spectrometry (LC-MS/MS) under the conditions presented in Appendix A. The preadministration nicotine concentrations in all formulations used for the study were within 10% of the target concentrations; sample analysis results are reported in Appendix A.

## B.2 Animal Source and Welfare

Male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (approximately 10 weeks old) were obtained from Envigo (Indianapolis, IN). Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee. Animals were housed in a facility that is fully accredited by AAALAC International. Animal procedures were in accordance with the Guide for the Care and Use of Laboratory Animals.^76^ Animals were quarantined immediately upon receipt. During the approximately 4-day quarantine period, all animals were observed twice daily for morbidity and mortality. Randomization was stratified by body weight to produce similar group mean weights using Provantis software (Instem, Version 8.6.1.2). Each study animal was assigned a unique identification number by the randomization program and identified by a cage card and an indelible ink tail marking.

## B.3 Study Design and Dose Administration

For each group, three animals per sex were administered a single gavage dose, either freebase (-)-nicotine or NBD in ASTM Type I water at a dose of 0.5 mg/kg. Gavage dosing was administered using a 15-gauge gavage needle with a 3 mL syringe. Dosing volumes were 5 mL/kg body weight. Animals were weighed on the day before dosing during randomization to calculate dosing volume. Because the tartrate salt crystallizes as the dihydrate, a monoisotopic mass of 498.2 g/mol was used for calculating freebase (-)-nicotine concentrations. Freebase (-)-nicotine represents 32.56% of the monoisotopic mass of the NBD compound. Morbidity/mortality checks were performed on all animals twice daily (prior to 10 a.m. and at or after 2 p.m., separated by at least 6 hours) during the study, except for the day of receipt and the day of study termination. Clinical observations for signs of toxicity were recorded prior to dose administration. Details of the study design and animal maintenance are summarized in Table B-1.

Table B-1 Experimental Design and Materials and Methods in the Toxicokinetic Study of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate

Freebase (-)-Nicotine | Nicotine Bitartrate Dihydrate
Study Laboratory
Battelle (West Jefferson, OH) | Same as freebase (-)-nicotine
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | Same as freebase (-)-nicotine
Animal Source
Envigo (Indianapolis, IN) | Same as freebase (-)-nicotine
Time Held Before Studies
4 days | Same as freebase (-)-nicotine
Average Age When Studies Began
10 weeks | Same as freebase (-)-nicotine
Date of Dosing
June 28, 2016 (male rats and female rats) | Same as freebase (-)-nicotine
Duration of Dosing
Single dose administered via gavage over 5 minutes | Single dose administered via gavage over 7 minutes
Size of Study Groups
Three male rats and three female rats | Same as freebase (-)-nicotine
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as freebase (-)-nicotine
Animals per Cage
1 | Same as freebase (-)-nicotine
Method of Animal Identification
Cage card and tail mark | Same as freebase (-)-nicotine
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as freebase (-)-nicotine
Water
Tap water (West Jefferson, OH municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as freebase (-)-nicotine
Cages
Upon receipt: solid polycarbonate cage (Lab Products, Inc., Seaford, DE), changed at least twice weekly During study period: Raturn Housing System of the Culex (BASi, West Lafayette, IN), changed at least twice weekly | Same as freebase (-)-nicotine
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as freebase (-)-nicotine
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as freebase (-)-nicotine
Dose
0.5 mg/kg administered via gavage (prepared in ASTM Type I water at concentration of 0.1 mg/mL); 5 mL/kg dosing volume. Dosing volumes were calculated based on body weights obtained on the day prior to dose administration. | Same as freebase (-)-nicotine
Type and Frequency of Observation
Observed twice daily except for day of receipt and day of study termination. Weighed on the day prior to dose administration (during randomization). Clinical observations for signs of toxicity were recorded prior to dose administration. | Same as freebase (-)-nicotine
Internal Concentration Assessment
Blood samples were collected via catheter from three animals at each of 15 time points (predose and at 0.08, 0.25, 0.5, 0.75, 1, 2, 4, 6, 8, 10, 12, 24, 48, and 72 hours postdose). Plasma was harvested from blood samples via centrifugation within 1 hour of blood collection. Plasma was evaluated for nicotine and cotinine (major metabolite) concentrations. Plasma was also qualitatively monitored for the following metabolites: trans-3’-hydroxycotinine, cotinine-N-oxide, cotinine N-β-D-glucuronide, norcotinine, nornicotine, trans-3’-hydroxycotinine-O-β-D-glucuronide, nicotine-1’-oxide, and nicotine N-β-D-glucuronide. | Blood samples were collected via catheter from three animals at 15 time points (predose and at 0.08, 0.25, 0.5, 0.75, 1, 2, 4, 6, 8, 10, 12, 24, 48, and 72 hours postdose), with one deviation: Animal 253 (female rat dosed with NBD) did not undergo blood sample collection at the 72-hour postdose time point. Plasma was harvested from blood samples via centrifugation within 1 hour of blood collection. Plasma was evaluated for nicotine and cotinine (major metabolite) concentrations. Plasma was also qualitatively monitored for the following metabolites: trans-3’-hydroxycotinine, cotinine-N-oxide, cotinine N-β-D-glucuronide, norcotinine, nornicotine, trans-3’-hydroxycotinine-O-β-D-glucuronide, nicotine-1’-oxide, and nicotine N-β-D-glucuronide.
Toxicokinetic Analysis
Plasma concentration-versus-time data were evaluated for aberrant concentration and time point values, as well as for any evidence of misdosing. Arithmetic and semilog plots of the plasma concentration-versus-time data sets were prepared for nicotine and cotinine. The concentration-versus-time profiles were analyzed using noncompartmental analysis with extravascular input (WinNonlin, Version 8.0, Certara, Princeton, NJ). Plasma toxicokinetic parameters were estimated for nicotine and cotinine in male and female animals. | Same as freebase (-)-nicotine

NBD = nicotine bitartrate dihydrate.

Blood samples (approximately 250 μL) were collected prior to dosing (predose) and at 14 time points after dose administration (0.08, 0.25, 0.5, 0.75, 1, 2, 4, 6, 8, 10, 12, 24, 48, and 72 hours postdose) from each animal that had a blood collection catheter placed in the carotid artery. Animals were conscious and freely moving during the blood collection periods while samples were automatically collected with the Culex instrument (BASi, West Lafayette, IN). Blood samples were collected from three animals at each of the 15 time points, except for the 72-hour time point when blood samples from only two female rats dosed with NBD were collected. Each blood sample was transferred into a tripotassium ethylenediaminetetraacetic acid-containing tube by the Culex and maintained at a refrigerated temperature (approximately 5°C) until it was separated into plasma by centrifugation (within 1 hour of blood collection). Plasma was placed into cryovials, stored on dry ice, and then transferred to an approximately −70°C freezer until analysis.

Concentrations of nicotine and cotinine, a major metabolite of nicotine, were measured by LC-MS/MS (Appendix A). Samples below the limit of detection (LOD) were designated as below the LOD (BLOD). With one exception due to a missing sample at 72 hours (due to patency issues), blood samples were collected from at least three animals at 15 time points, except for the 72-hour time point at which samples were collected from only two female rats dosed with NBD. For each time point, the mean was calculated.

Additionally, the following metabolites were qualitatively monitored in plasma samples: trans-3’-hydroxycotinine, cotinine-N-oxide, cotinine N-β-D-glucuronide, norcotinine, nornicotine, trans-3’-hydroxycotinine-O-B-D-glucuronide, nicotine-1’-oxide, and nicotine N-β-D-glucuronide. The standards used for this analysis [S-(-)-cotinine, nicotine-d3, cotinine-d3, trans-3’-hydroxy cotinine, cotinine-N-oxide, cotinine N-β-D-glucuronide, (R,S)-norcotinine, (R,S)-nornicotine, trans-3’-hydroxy cotinine O-β-D-glucuronide, (1’S,2’S)-nicotine 1’-oxide, and nicotine N-β-D-glucuronide] were purchased from Toronto Research Chemicals, Inc. (Toronto, Ontario, Canada).

## B.4 Toxicokinetic Analysis

Plasma concentration-versus-time data were evaluated for aberrant concentration and time point values as well as for any evidence of misdosing. Individual animal data were examined for acceptable agreement between the target and actual collection times (i.e., within 5% for time points ≤4 hours and within 15 minutes for time points >4 hours). If substantial evidence indicated an explanation for potential aberrant concentrations, the value was reported but flagged with an explanation for its omission from the data set. Concentration-versus-time data sets for both nicotine and cotinine were evaluated using noncompartmental analysis (NCA) (WinNonlin, Version 8.0, Certara, Princeton, NJ) with extravascular input. No weighting factors were used to obtain the initial estimates for NCA. The software algorithm was allowed to select the points used to calculate slope of the terminal linear phase by determining an optimal determination coefficient (R^2^). A glossary of kinetic symbols and definitions is provided in Table B-2.

Table B-2 Analytical Glossary of Kinetic Symbols and Definitions Used in Toxicokinetic Studies

Parameter | Noncompartmental Analysis | Definition
C_max_observed_ | C_max_ | Observed maximum plasma concentration
T_max_observed_ | T_max_ | Time at which observed C_max_ occurs
T_last_ | T_last_ | Time at which last plasma concentration occurs
Lambda_z | Lambda_z | Noncompartmental analysis (NCA) terminal elimination rate constant, NCA k_e_ or k_elim_
Half-life | HL_Lambda_z | Lambda z half-life, t_1/2_, the terminal elimination half-life based on noncompartmental analysis
Cl | Cl_pred | Clearance of central compartment
Cl1_F | Cl_F_pred | Apparent clearance of the central compartment, also Cl_F for gavage groups in noncompartmental model
V1 | Vz_pred | Volume of distribution of the central compartment, includes Vd and V volume of distribution
V1_F | Vz_F_pred | Apparent volume of distribution for the central compartment, includes Vd_F, V_F for oral groups, and Vc_F
MRT | MRT_INF_pred_ | Mean residence time
AUC_0-T | AUC_last_ | Area under the plasma-concentration-versus-time curve, AUC, from time t_i_ (initial) to t_f_ (final), AUC_last_
AUC_∞___predicted_ | AUC_INF_pred_ | Area under the plasma-concentration-versus-time curve, AUC, extrapolated

## B.5 Toxicokinetic Results

Following a single oral administration of freebase (-)-nicotine and NBD at 0.5 mg/kg in rats, the absorption of nicotine was rapid, occurring within the first hour for all but one animal. Comparisons of male and female rats revealed no apparent sex-related differences in toxicokinetic parameters, including systemic exposure parameters such as the maximum plasma concentration (C_max_) and area under the plasma-concentration-versus-time curve (AUC), of nicotine following either freebase (-)-nicotine or NBD administration (Table B-3). In addition, mean toxicokinetic parameters, including systemic exposure, were similar when comparing freebase (-)-nicotine and NBD. The only difference greater than twofold was the half-life for female rats, which was only 2.1-fold longer following NBD administration (3.82 versus 1.83 hours) and likely not biologically relevant.

Following oral administration of freebase (-)-nicotine and NBD in rats, concentrations of the metabolite cotinine rose with a T_max_observed_ of 4–5.33 hours for all animals (Table B-4). When compared to nicotine T_max_observed_, which was typically between 0.5 and 1 hour, this difference suggested a slow conversion of nicotine to cotinine. Comparisons of male and female rats revealed no apparent sex-related effects on the toxicokinetic parameters or systemic exposure of cotinine following freebase (-)-nicotine or NBD administration. Cotinine, following either freebase (-)-nicotine or NBD administration, for both male and female rats, had a longer half-life (1.4- to 3.4-fold) and greater systemic exposure (C_max_observed_ 2.6- to 4.0-fold; AUC_last ∞___predicted_ 8.8- to 11.6-fold) than nicotine; systemic exposure was similar when comparing freebase (-)-nicotine and NBD.

In conclusion, toxicokinetic parameters, including systemic exposure, were similar in male and female rats following a single oral administration of freebase (-)-nicotine and NBD at 0.5 mg/kg. Because freebase (-)-nicotine is less stable than NBD in solutions and the salt is easy to handle, NBD was selected as the test article.

Table B-3 Summary of Plasma Toxicokinetic Parameters of Nicotine in Male and Female Rats Following Gavage Administration of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate^a^

Parameter | Freebase (-)-Nicotine (0.5 mg/kg) | | NBD (0.5 mg/kg)
Parameter | Male | Female | Male | Female
C_max___observed_ (ng/mL) | 50.5 ± 5.3 | 61.7 ± 12.0 | 49.5 ± 7.9 | 36.7 ± 3.0
T_max___observed_ (hr) | 0.917 ± 0.083 | 0.583 ± 0.083 | 0.667 ± 0.083 | 0.917 ± 0.546
Half-life (hr) | 2.70 ± NA | 1.83 ± 0.41 | 3.25 ± 1.09 | 3.82 ± NA
Cl1_F (mL/hr/kg) | 12,100 ± NA | 10,800 ± 600 | 10,800 ± 900 | 10,400 ± NA
V1_F (mL/kg) | 43,900 ± NA | 28,800 ± 6,600 | 48,000 ± 12,900 | 50,900 ± NA
AUC_last_ (hr*ng/mL) | 129 ± 6 | 153 ± 16 | 128 ± 9 | 126 ± 15
AUC_∞___predicted_ (hr*ng/mL) | 169 ± NA | 186 ± 10 | 188 ± 15 | 211 ± NA

NBD = nicotine bitartrate dihydrate; C_max_observed_ = observed maximum plasma concentration; T_max_observed_ = time at which observed C_max_ occurs; NA = not applicable; Cl1_F = apparent clearance of the central compartment; V1_F = apparent volume of distribution for the central compartment; AUC_last_ = area under the plasma-concentration-versus-time curve from initial to final; AUC_∞_predicted_ = area under the plasma-concentration-versus-time curve extrapolated to time equals infinity.

^a^ Data are presented as mean of individual animal toxicokinetic parameters ± standard error.

Table B-4 Summary of Plasma Toxicokinetic Parameters of Cotinine in Male and Female Rats Following Gavage Administration of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate^a^

Parameter | Freebase (-)-Nicotine (0.5 mg/kg) | | NBD (0.5 mg/kg)
Parameter | Male | Female | Male | Female
C_max___observed_ (ng/mL) | 150 ± 21 | 160 ± 10 | 136 ± 21 | 147 ± 6
T_max___observed_ (hr) | 4.00 ± 0.00 | 4.67 ± 0.67 | 4.00 ± 0.00 | 5.33 ± 0.67
Half-life (hr) | 3.94 ± 0.44 | 6.17 ± 0.73 | 4.53 ± 0.49 | 5.52 ± 0.69
Cl1_F (mL/hr/kg) | 1,250 ± 40 | 933 ± 60 | 1,210 ± 80 | 962 ± 58
V1_F (mL/kg) | 7,110 ± 760 | 8,210 ± 670 | 7,960 ± 1140 | 7,690 ± 1190
AUC_last_ (hr*ng/mL) | 1,280 ± 80 | 1,750 ± 130 | 1,520 ± 100 | 1,940 ± 120
AUC_∞___predicted_ (hr*ng/mL) | 1,600 ± 50 | 2,160 ± 150 | 1,660 ± 100 | 2,090 ± 130

NBD = nicotine bitartrate dihydrate; C_max_observed_ = observed maximum plasma concentration; T_max_observed_ = time at which observed C_max_ occurs; Cl1_F = apparent clearance of the central compartment; V1_F = apparent volume of distribution for the central compartment; AUC_last_ = area under the plasma-concentration-versus-time curve from initial to final; AUC_∞_predicted_ = area under the plasma-concentration-versus-time curve extrapolated to time equals infinity.

^a^ Data are presented as mean of individual animal toxicokinetic parameters ± standard error.