# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate

Nicotine as freebase (-)-nicotine and nicotine bitartrate dihydrate (NBD) were obtained from Siegfried (Zofingen, Switzerland) via Interchem Corporation (Paramus, NJ) in single lots (lots 1515L008 and 1531H012, respectively). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the nicotine studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 1515L008 of freebase (-)-nicotine was a colorless to yellow or brownish liquid prior to handling. It arrived in two bottles, and the bottles were not combined because of the hazardous nature of the material. The bottles were homogenized by inverting them 10 times to mix. Bulk freebase (-)-nicotine was stored at room temperature (13°C–25°C), protected from light, and under inert gas with desiccant.

Lot 1531H012 of NBD was a white or almost-white powder. It was homogenized by first removing the test article bag from the outer container and then sealing the inner plastic bag of the test article in a second plastic bag. The contents were kneaded for approximately 1 minute, and then the bag was rotated 180° and the contents were kneaded again for approximately 1 minute. This process of rotating and kneading was repeated six times to homogenize the material. The homogenized test article was then repackaged into 10 1-L amber high-density polyethylene (HDPE) bottles. The containers were capped and sealed with tape and then stored at room temperature (13°C–25°C) with desiccant.

The lot identities were confirmed using infrared (IR), ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopies, and high-performance liquid chromatography (HPLC) with mass spectrometry (MS). The IR spectra (Figure A-1, Figure A-4) were consistent with the structure of NBD for lot 1531H012 (no reference spectrum available) and with the freebase (-)-nicotine reference spectrum (No. DLX 1359, Bio-Rad “Know It All” v.14.1.209.0) for lot 1515L008. The ^1^H and ^13^C spectra (Figure A-2, Figure A-3, Figure A-5, Figure A-6) were consistent with the structures predicted by the Advanced Chemistry Development spectral prediction program (Version 14.00).^73^

HPLC/MS supported the identity of nicotine in both lots, as the mass spectra and fragmentation were consistent with nicotine (Table A-1, System A). Elemental analysis was performed by Galbraith Laboratories (Knoxville, TN). The relative amounts of carbon, hydrogen, nitrogen, and oxygen for lot 1531H012 (43.43%, 5.93%, 45.37%, and 5.55%, respectively) were within 3% of the theoretical values for NBD. The relative amounts of carbon, hydrogen, and nitrogen for lot 1515L008 (73.69%, 8.32%, and 17.10%, respectively) were within 4% of the theoretical values for freebase (-)-nicotine.

The moisture content of lots 1515L008 and 1531H012 was determined by Karl Fischer titration and performed at Galbraith Laboratories (Knoxville, TN). The specific rotation and water analyses were performed at Exova Inc. (Santa Fe Springs, CA). Differential scanning calorimetry (DSC) was attempted for both lots, but the analysis of NBD resulted in broad duplicate overlapping peaks due to the dihydrate salt complex nature of the compound, and accurate purity and melting points could not be determined. The volatile content was determined by thermogravimetric analysis (TGA). The purity profiles were determined using HPLC with ultraviolet (UV) detection. Additionally, the purity of freebase (-)-nicotine lot 1515L008 was supported by gas chromatography with flame ionization detection (GC/FID).

For freebase (-)-nicotine lot 1515L008, Karl Fischer titration yielded an average water content of 0.18 ± 0.01( d- )% ( d- is the deviation between two samples). The specific rotation analysis indicated an average of −133.2°C, which was 4°C different from the value reported on the certificate of analysis (COA) from the manufacturer (−137.1°C) but consistent with the specification of freebase (-)-nicotine (−143°C to −130°C).^74^ The water analysis indicated 0.23% water was present in the test article, congruent with Galbraith’s Karl Fischer titration results but slightly higher than the 0.02% reported on the COA. DSC measured the boiling point as 244.9°C, which was consistent with freebase (-)-nicotine’s known boiling point.^4^ TGA did not detect volatile or nonvolatile impurities. The purity of the two containers was determined separately by HPLC/UV at 254 nm and was 99.6% for both containers (Table A-1, System B). Two impurity peaks representing 0.4% of the total area were present in the chromatograms. Furthermore, ^1^H NMR confirmed identical structures and purity between the two containers. Impurity signals detected near 3.71 ppm and 1.23 ppm of the ^1^H NMR spectra were indicative of an ethyl group and assigned to the probable presence of ethanol. GC/FID (Table A-2, System E) also detected one impurity present at 0.27%, resulting in an overall purity of 99.7%. The purity values measured by HPLC/UV and GC/FID were consistent with the 99.3% purity reported on the COA. Given the ^1^H NMR results, the impurities measured by HPLC/UV and GC/FID were likely ethanol.

For NBD lot 1531H012, Karl Fischer titration yielded an average water content of 8.97 ± 0.49( d- )%, which was within 2% of the theoretical value (7.23%), based on the molecular formula of NBD, and slightly higher than the 7.41% reported on the COA. The specific rotation analysis indicated an average degree of +23.0°C, which was consistent with the 22.8°C reported on the COA. The water analysis indicated 7.2% water, which was consistent with the 7.41% reported on the COA. TGA results corresponded with literature reports for NBD and indicated no detectable volatile or nonvolatile impurities. The purity determined by HPLC/UV at 254 nm was 100%, which was consistent with the 100% purity reported on the COA (Table A-1, System B). A second HPLC system using UV detection at 210 nm was used to estimate purity—no impurity peaks representing >0.1% of the total peak area were detected (Table A-1, System C).

Accelerated stability studies of freebase (-)-nicotine and NBD were conducted on lots 1515L008 and 1531H012, respectively. Samples of each test article were stored in four individual 4-mL amber glass vials for 15 days at approximately 60°C, room temperature, approximately 5°C, and approximately −20°C. The appearance of each sample was noted before and after storage, and purity was analyzed with HPLC/UV at 210 nm (Table A-1, System C). Freebase (-)-nicotine samples were stable for at least 15 days at approximately −20°C, 5°C, and room temperature. Storing freebase (-)-nicotine at approximately 60°C reduced the purity to 96.7%. NBD samples were stable when stored in sealed glass containers for at least 15 days at temperatures of −20°C to 60°C.

## A.2 Preparation and Analysis of Dose Formulations

The dose formulations for the toxicokinetic studies were prepared once at Battelle (Columbus, OH) by mixing freebase (-)-nicotine or NBD in ASTM Type I water at a concentration of 0.1 mg/mL. Test articles were weighed into a mixing container, diluted to the final volume with vehicle, and stirred with a magnetic stir plate and stir bar until dissolved. While stirring, 10-mL aliquots of each formulation were dispensed for analysis and retention (archive) samples. Final formulations were dispensed into appropriately labeled individual amber glass bottles for dosing and then sealed and placed in a secondary container. The freebase (-)-nicotine formulations were stored at 2°C–8°C, and the NBD formulations were stored at room temperature (Table A-3). Formulations were analyzed prior to dosing by liquid chromatography with tandem mass spectrometry (LC-MS/MS) (Table A-1, System D), using a calibration curve from 0.01 to 0.4 µg/mL of nicotine in diluent (10:90 acetonitrile:20 mM ammonium bicarbonate in water [v/v]) and nicotine-d3 (C/D/N Isotopes, Pointe-Claire, Quebec, Canada) as an internal standard (IS). The preadministration nicotine concentrations in all formulations used for the study were within 10% of the target concentrations (Table A-5).

Dose preparation and analysis for the 4-week studies are not presented in this report. The dose formulations for the 3-month studies were prepared weekly at the Ramazzini Institute (Bologna, Italy) by mixing NBD with tap water to obtain the desired concentrations for each species (Table A-4).

For the rat study, formulations were prepared at concentrations of 0, 1.56, 3.12, 6.25, 12.5, and 25 mg nicotine/L. For the mouse study, formulations were prepared at concentrations of 0, 6.25, 12.5, 25, 50, and 100 mg/L. The typical formulation volume prepared was 50 L. Dose calculations used to prepare the formulations were based on the molecular weight of nicotine, and weights were normalized to salt molecular weight. Dose formulations were stored at room temperature in HDPE plastic bottles, covered with black plastic foil to avoid light exposure, and dispensed to the animals daily in dark glass bottles. Aliquots (from three different time points) of each preadministration formulation dose were sent frozen in an insulated container to Battelle (Columbus, OH) for analysis, where they were stored at −30°C to −15°C until analyzed.

Preadministration formulations for the 3-month studies were analyzed by LC-MS/MS (Table A-1, System D) using a calibration curve from 0.01 mg/L to 0.4 mg/L of nicotine in diluent (ASTM Type I water) and nicotine-d3 as an IS. Each formulation dose was diluted with ASTM Type I water into the quantitation range of the analytical method. Blanks of ASTM Type I water were used to assess system suitability. The results of the preadministration formulation analysis of the 3-month studies are shown in Table A-6 (rats) and Table A-7 (mice). Multiple formulations had results outside the typical NIEHS acceptance criteria for accuracy and precision (average concentration within 10% of the target concentration and relative standard deviation [RSD] values within 5%). However, these deviations were not considered to significantly affect the studies. All mouse formulations were within 10% of the target concentration, and all rat formulations were within 10%, except for the 1.56 mg/L formulations from the first and second shipment, which were 59.0% and 15.7% above target, respectively.

Prior to study start, the degradation of nicotine in drinking water formulations was investigated. At the lowest exposure concentration, some loss of nicotine was observed when formulations were prepared in tap water (Columbus, OH) but not in deionized water, and this was attributed to the presence of chlorine in tap water.^75^ Because in Europe, where the study laboratory was located, water disinfection is done mainly via ozonation with much lower levels of chlorine, tap water was used to prepare formulations.

The RSD values of all formulations were within the NIEHS acceptance limit of 5%, with the exception of the 50 mg/L formulation from the 3-month mouse study analyzed on March 24, 2017; the 12.5, 25, and 50 mg/L formulations from the 3-month mouse study analyzed on April 14, 2017; the 6.25 mg/L formulation from the perinatal and 3-month rat study analyzed from April 28, 2017, to May 1, 2017; and the 6.25, 12.5, and 25 mg/L formulations from the 3-month mouse study analyzed on May 26, 2017. After removing two outliers by the Q-test, these formulations had RSD values from 6.2% to 9.2% (values not shown). The control (0 mg/mL) formulations were below the limit of quantitation (BLOQ).

Table A-1 Liquid Chromatography Systems Used in the Toxicokinetic, Four-week, and Three-month Studies of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate

Chromatography | Detection System | Column | Mobile Phase
System A
High-performance liquid chromatography | Mass spectrometry, positive ion | Phenomenex Gemini C18 (150 × 4.6 mm ID, 5 µm particle size) | A: 10 mM ammonium bicarbonate, pH 10.5 (aq) B: Acetonitrile Gradient program: A:B 95:5 for 3 minutes; 95:5 to 75:25 in 25 minutes; 75:25 to 60:40 in 4 minutes; 60:40 to 95:5 in 1 minute; hold at 95:5 for 3 minutes 1 mL/min flow rate
System B
High-performance liquid chromatography | Ultraviolet (254 nm) | Phenomenex Gemini C18 (150 × 4.6 mm ID, 5 µm particle size) | A: 10 mM ammonium bicarbonate, pH 10.5 (aq) B: Acetonitrile Gradient program: A:B 95:5 for 3 minutes; 95:5 to 75:25 in 25 minutes; 75:25 to 60:40 in 4 minutes; 60:40 to 95:5 in 1 minute; hold at 95:5 for 3 minutes 1 mL/min flow rate
System C
High-performance liquid chromatography | Ultraviolet (210 nm) | Thermo Scientific Acclaim Trinity P1 (50 × 3 mm ID, 3 µm particle size) | A: 4 mmol dibasic sodium phosphate, 20 mmol monobasic sodium phosphate, 81 µmol tetrasodium pyrophosphate decahydrate, pH 6.3 (aq) B: Acetonitrile Gradient program: A:B Isocratic 75:25 0.6 mL/min flow rate
System D
High-performance liquid chromatography | Tandem mass spectrometry, positive ion | Phenomenex Kinetex, XB-C18, (150 × 4.6 mm ID, 5 μm particle size) Phenomenex Security Guard, C18, 4 × 2 mm | A: 10 mM ammonium bicarbonate (aq) B: Methanol Gradient program: A:B 95:5 for 0.1 minute; 95:5 to 20:80 in 5 minutes; hold at 20:80 for 2 minutes; 20:80 to 95:5 in 0.5 minutes; hold at 95:5 for 4.5 minutes 400 µL/min flow rate

ID = internal diameter.

Table A-2 Gas Chromatography Systems Used in the Toxicokinetic, Four-week, and Three-month Studies of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate

Detection System | Column | Carrier Gas | Oven Temperature Program
System E
Flame ionization | Restek Stabilwax (30 m × 0.32 mm ID, 1-µm film thickness) | Helium, ~1 mL/min | 50°C, no hold, then 10°C/min to 250°C, held for 5 minutes

ID = internal diameter.

Table A-3 Preparation and Storage of Dose Formulations in the Toxicokinetic Study of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate

Freebase (-)-Nicotine | Nicotine Bitartrate Dihydrate
Preparation
Formulations for gavage administration were prepared in ASTM Type I water at a concentration of 0.1 mg/mL by first weighing the appropriate amount of test article into a mixing container and then diluting to the final volume with vehicle. Formulations were stirred with a magnetic stir plate and stir bar until the test article dissolved. The mixed formulations were dispensed into appropriately labeled individual amber glass bottles for dosing and then sealed and placed in a secondary container. | Same as freebase (-)-nicotine
Chemical Lot Number
1515L008 (Siegfried, Zofingen, Switzerland) | 1531H012 (Siegfried, Zofingen, Switzerland)
Storage Conditions
Individual sealed amber glass bottles at 2°C–8°C | Individual sealed amber glass bottles at room temperature
Study Laboratory
Battelle (Columbus, OH) | Same as freebase (-)-nicotine

Table A-4 Preparation and Storage of Dose Formulations in the Three-month Studies of Nicotine Bitartrate Dihydrate

Preparation
The dose formulations were prepared by mixing nicotine bitartrate dihydrate with tap water and then diluting to the five required final concentrations.
Chemical Lot Number
1531H012 (Siegfried, Zofingen, Switzerland)
Storage Conditions
During the study, dose formulations were stored at room temperature in high-density polyethylene plastic bottles, covered with black plastic foil. Samples were shipped frozen from the Ramazzini Institute to Battelle in insulated containers and stored frozen (−30°C to −15°C) at Battelle prior to analysis.
Study Laboratory
Cesare Maltoni Cancer Research Center, Ramazzini Institute (Bologna, Italy)
Analytical Laboratory
Battelle (Columbus, OH)

Table A-5 Results of Preadministration Analyses of Dose Formulations for Male and Female Rats in the Toxicokinetic Study of Freebase (-)-Nicotine and Nicotine Bitartrate Dihydrate

| Date Analyzed | Target Concentration (mg/mL) | Determined Concentration (mg/mL)^a^ | Difference from Target (%)
Freebase (-)-Nicotine | June 21, 2016 | 0.1 | 0.103 ± 0.001 | 2.6
Nicotine Bitartrate Dihydrate^b^ | June 21, 2016 | 0.1 | 0.101 ± 0.002 | 0.6

^a^ Results of triplicate analyses.

^b^ Nicotine bitartrate dihydrate target concentration is corrected for salt and water with a correction factor of 0.3255 (162.2/498.2 g/mol).

Table A-6 Results of Preadministration Analyses of Dose Formulations for Male and Female Rats in the Perinatal and Three-month Study of Nicotine Bitartrate Dihydrate

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
April 22, 2017 | April 28, 2017–May 1, 2017 | 0 | BLOQ | NA
April 22, 2017 | April 28, 2017–May 1, 2017 | 1.56 | 2.48 ± 0.13 | 59.0
April 22, 2017 | April 28, 2017–May 1, 2017 | 3.12 | 3.00 ± 0.16 | −3.8
April 22, 2017 | April 28, 2017–May 1, 2017 | 6.25 | 6.27 ± 0.42 | 0.4
April 22, 2017 | April 28, 2017–May 1, 2017 | 12.5 | 12.0 ± 0.5 | −3.9
April 22, 2017 | April 28, 2017–May 1, 2017 | 25.0 | 24.8 ± 1.2 | −0.9
May 15, 2017 | May 26, 2017 | 0 | BLOQ | NA
May 15, 2017 | May 26, 2017 | 1.56 | 1.80 ± 0.03 | 15.7
May 15, 2017 | May 26, 2017 | 3.12 | NA | NA
May 15, 2017 | May 26, 2017 | 6.25 | NA | NA
May 15, 2017 | May 26, 2017 | 12.5 | NA | NA
May 15, 2017 | May 26, 2017 | 25.0 | NA | NA
July 24, 2017 | August 2, 2017 | 0 | BLOQ | NA
July 24, 2017 | August 2, 2017 | 1.56 | 1.53 ± 0.05 | −1.7
July 24, 2017 | August 2, 2017 | 3.12 | 3.28 ± 0.05 | 5.3
July 24, 2017 | August 2, 2017 | 6.25 | 6.19 ± 0.28 | −1.0
July 24, 2017 | August 2, 2017 | 12.5 | 12.8 ± 0.2 | 2.7
July 24, 2017 | August 2, 2017 | 25.0 | 25.3 ± 0.8 | 1.2

BLOQ = below the limit of quantitation; NA = not applicable.

^a^ Results of triplicate analyses.

Table A-7 Results of Preadministration Analyses of Dose Formulations for Male and Female Mice in the Three-month Study of Nicotine Bitartrate Dihydrate

Date Formulated | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
February 21, 2017 | March 10, 2017 | 0 | BLOQ | NA
February 21, 2017 | March 10, 2017 | 6.25 | 6.30 ± 0.13 | 0.8
February 21, 2017 | March 10, 2017 | 12.5 | 12.7 ± 0.2 | 4.7
February 21, 2017 | March 10, 2017 | 25.0 | 25.5 ± 0.1 | 1.9
February 21, 2017 | March 10, 2017 | 50.0 | 50.3 ± 1.0 | 0.5
February 21, 2017 | March 10, 2017 | 100.0 | 100 ± 2 | 0.3
March 20, 2017 | March 24, 2017 | 0 | BLOQ | NA
March 20, 2017 | March 24, 2017 | 6.25 | 6.54 ± 0.33 | 4.7
March 20, 2017 | March 24, 2017 | 12.5 | 12.3 ± 0.2 | −1.6
March 20, 2017 | March 24, 2017 | 25.0 | 25.0 ± 0.6 | 0.1
March 20, 2017 | March 24, 2017 | 50.0 | 51.5 ± 0.2^b^ | 3.0
March 20, 2017 | March 24, 2017 | 100.0 | 101 ± 2 | 0.6
April 7, 2017 | April 14, 2017 | 0 | BLOQ | NA
April 7, 2017 | April 14, 2017 | 6.25 | 6.05 ± 0.29 | −3.1
April 7, 2017 | April 14, 2017 | 12.5 | 11.5 ± 0.8 | −7.9
April 7, 2017 | April 14, 2017 | 25.0 | 24.5 ± 2.1 | −1.9
April 7, 2017 | April 14, 2017 | 50.0 | 49.5 ± 3.6 | −0.9
April 7, 2017 | April 14, 2017 | 100.0 | 99.0 ± 3.6 | −1.0
May 19, 2017 | May 26, 2017 | 0 | BLOQ | NA
May 19, 2017 | May 26, 2017 | 6.25 | 6.41 ± 0.59 | 2.6
May 19, 2017 | May 26, 2017 | 12.5 | 12.4 ± 0.8 | −0.5
May 19, 2017 | May 26, 2017 | 25.0 | 26.2 ± 0.4^b^ | 4.7
May 19, 2017 | May 26, 2017 | 50.0 | 52.5 ± 1.5 | 5.0
May 19, 2017 | May 26, 2017 | 100.0 | 104 ± 1 | 4.5

BLOQ = below the limit of quantitation; NA = not applicable.

^a^ Results of triplicate analyses.

^b^ Calculation performed with one outlier excluded.

Figure A-1

Infrared Absorption Spectrum of Nicotine Bitartrate Dihydrate

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Nicotine Bitartrate Dihydrate

Figure A-3

^13^C Nuclear Magnetic Resonance Spectrum of Nicotine Bitartrate Dihydrate

Figure A-4

Infrared Absorption Spectrum of Freebase (-)-Nicotine

Figure A-5

^1^H Nuclear Magnetic Resonance Spectrum of Freebase (-)-Nicotine

Figure A-6

^13^C Nuclear Magnetic Resonance Spectrum of Freebase (-)-Nicotine