# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

ISSN: 2768-5632

DOI: https://doi.org/10.22427/NIEHS-10

Report Series: NIEHS Report Series

Report Series Number: 10

Official citation: Auerbach SS, Ballin JD, Blake JC, Browning DB, Collins BJ, Cora MC, Fernando RA, Fostel JM, Liu YF, Luh J, Machesky NJ, Prince LM, Roberts GK, Shipkowski KA, Silinski MAR, Skowronek AJ, Sparrow BR, Toy H, Waidyanatha S, Watson ATD. 2023. NIEHS report on the in vivo repeat dose biological potency study of perfluorohexanesulfonamide (CASRN 41997-13-1) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (gavage studies). Research Triangle Park, NC: National Institute of Environmental Health Sciences. NIEHS Report 10.