# Summary

Perfluorohexanesulfonamide (PFHxSAm) is a member of the per- and polyfluoroalkyl class of compounds to which humans are widely exposed. A review of the literature did not identify toxicological data for estimating the potential adverse health effects of PFHxSAm. This study used a transcriptomic approach and standard toxicological endpoints to estimate the in vivo biological potency of PFHxSAm.

A subset of standard toxicological endpoints (cholesterol concentration and neutrophil count in male rats; sorbitol dehydrogenase activity, total thyroxine concentration, and aspartate aminotransferase activity in female rats) exhibited benchmark dose (BMD) values much lower than would be expected given the endpoint-specific no-observed-effect level and lowest-observed-effect level values. Expert review of the data suggests that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and were likely an anomalous product of the BMD modeling approach.

Taking this into account, the most sensitive apical endpoint in male rats was a decrease in total thyroxine concentration with an estimated BMD and benchmark dose lower confidence limit (BMD_L_) of 7.264 (5.024) mg/kg. Increases in absolute and relative liver weights were the next most sensitive apical endpoint changes observed in male rats with BMDs (BMD_L_s) of 8.492 (5.426) and 16.251 (8.358) mg/kg, respectively. In female rats, there were no apical endpoints for which a BMD value could be reliably estimated.

Gene set-level transcriptional changes in the liver following PFHxSAm exposure were estimated to occur at a BMD (BMD_L_) as low as 0.520 (0.160) mg/kg in male rats, corresponding to negative regulation of myeloid cell differentiation (GO:0045638), and as low as 11.677 (5.931) mg/kg in female rats, corresponding to phenol-containing compound metabolic process (GO:0018958). The most sensitive liver gene for which a reliable BMD could be determined in male rats was Egr1 with a BMD (BMD_L_) of 0.750 (0.186) mg/kg, and A2m and Loc100911545/A2m in female rats, both with a BMD (BMD_L_) of 1.163 (0.179) mg/kg.

Gene set-level transcriptional changes in the kidney were estimated to occur at a BMD (BMD_L_) as low as 8.745 (5.224) mg/kg in male rats, corresponding to fat cell differentiation (GO:0045444), and as low as 10.324 (7.461) mg/kg in female rats, corresponding to regulation of cell division (GO:0051302). The most sensitive kidney gene for which a reliable BMD could be determined was Loc100911814/Spink1l with a BMD (BMD_L_) of 0.510 (0.212) mg/kg in male rats and Cdca3 with a BMD (BMD_L_) of 2.619 (0.978) mg/kg in female rats.

Under the conditions of this short-duration transcriptomic study in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats, the most sensitive point of departure with a reliable estimate in male rats was a transcriptional change in a gene, Loc100911814/Spink1l with a BMD (BMD_L_) of 0.510 (0.212) mg/kg. Gene set transcriptional changes provided potency estimates in the same range, while apical endpoints provided potency estimates higher than Loc100911814/Spink1l. In female rats, the most sensitive point of departure with a reliable estimate was a transcriptional change in the genes A2m and Loc100911545/A2m, both with a BMD (BMD_L_) of 1.163 (0.179) mg/kg. Gene set transcriptional changes provided potency estimates slightly higher than those of A2m and Loc100911545/A2m, while there were no apical endpoints with potency estimates that could be compared to A2m and Loc100911545/A2m.