# Results

## Animal Condition, Body Weights, and Organ Weights

Male and female rats administered 333 or 1,000 mg/kg body weight (mg/kg) of perfluorohexanesulfonamide (PFHxSAm) began exhibiting signs of overt toxicity on study day 1, which included red discharge from nose/snout and penis, clear or red discharge from eyes, labored breathing, pale appearance, salivation, hunched posture, prone positioning, and lethargy (Appendix F). In the 333 mg/kg group, three male rats and four female rats were found dead on study day 1, and the remaining rats were moribund and euthanized at that time due to severe toxicity. In the 1,000 mg/kg day group, one male rat was found dead on study day 0, four male rats and four female rats were found dead on study day 1, and the remaining female rat was moribund and euthanized at that time. Rats in the 0, 0.15, 0.5, 1.4, 4, 12, 37, and 111 mg/kg groups did not exhibit signs of overt toxicity, and all survived to study termination. No significant changes in terminal body weight for male or female rats occurred with exposure to PFHxSAm (Table 2).

Table 2 Summary of Body Weights of Male and Female Rats Administered Perfluorohexanesulfonamide for Five Days

Study Day^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 4^c^ | NA | NA
0 | 296.5 ± 4.4 | 297.3 ± 4.5 | 295.9 ± 1.6 | 303.7 ± 5.0 | 292.6 ± 3.8 | 304.1 ± 3.0 | 293.2 ± 4.0 | 298.5 ± 6.0 | 298.6 ± 3.4 | 293.8 ± 4.5 | ND | ND
5 | 311.0 ± 5.2 | 314.0 ± 5.1 | 315.5 ± 1.4 | 320.1 ± 4.8 | 308.2 ± 4.4 | 325.9 ± 4.7 | 308.6 ± 4.2 | 308.6 ± 3.9 | –^d^ | – | ND | ND
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 210.1 ± 5.4 | 209.1 ± 6.6 | 206.7 ± 3.9 | 205.2 ± 4.2 | 212.9 ± 7.1 | 206.8 ± 3.9 | 203.6 ± 4.6 | 207.0 ± 3.9 | 204.9 ± 4.4 | 203.6 ± 4.5 | ND | ND
5 | 221.0 ± 5.4 | 215.4 ± 7.5 | 211.0 ± 4.0 | 213.0 ± 6.5 | 219.0 ± 7.4 | 216.3 ± 6.2 | 208.2 ± 5.5 | 213.2 ± 4.0 | – | – | ND | ND

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Data are displayed as mean ± standard error of the mean; body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ One male rat was found dead on study day 0.

^d^ All male and female 333 and 1,000 mg/kg rats were found dead or moribund and euthanized by study day 1.

In male rats at study termination, a significant increase in absolute and relative liver weights occurred in dose groups ≥12 mg/kg; these endpoints had positive trends (Table 3). The benchmark doses (benchmark dose lower confidence limits)—BMDs (BMD_L_s)—for increased absolute and relative liver weights were 8.492 (5.426) and 16.251 (8.358) mg/kg, respectively. The BMDs for all organ weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values). Significant trend and pairwise comparisons were not observed in absolute or relative heart, right kidney, or left kidney weights (Appendix F).

Table 3 Summary of Liver Weights of Male Rats Administered Perfluorohexanesulfonamide for Five Days

Endpoint^a,b,c^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | –^d^ | – | NA | NA
Terminal Body Wt. (g) | 311.0 ± 5.2 | 314.0 ± 5.1 | 315.5 ± 1.4 | 320.1 ± 4.8 | 308.2 ± 4.4 | 325.9 ± 4.7 | 308.6 ± 4.2 | 308.6 ± 3.9 | – | – | ND | ND
Liver
Absolute (g) | 11.48 ± 0.31** | 12.00 ± 0.37 | 12.31 ± 0.30 | 12.48 ± 0.35 | 11.80 ± 0.35 | 13.14 ± 0.41** | 12.75 ± 0.30** | 14.31 ± 0.11** | – | – | 8.492 | 5.426
Relative (mg/g)^e^ | 36.88 ± 0.52** | 38.21 ± 0.78 | 39.03 ± 0.85 | 39.01 ± 1.22 | 38.26 ± 0.77 | 40.28 ± 0.78** | 41.33 ± 1.00** | 46.42 ± 0.86** | – | – | 16.251 | 8.358

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Descriptions of organ weight endpoints and changes are provided in Appendix E.

^b^ Data are displayed as mean ± standard error of the mean.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ All male and female 333 and 1,000 mg/kg rats were found dead or moribund and euthanized by study day 1.

^e^ Relative organ weights (organ weight-to-body weight ratios) are given as mg organ weight/g body weight.

In female rats at study termination, there were no organ weights that exhibited significant trend and pairwise comparisons (Appendix F).

## Clinical Pathology

In male rats, cholesterol concentration exhibited significant trend and pairwise comparisons. In female rats, both aspartate aminotransferase and sorbitol dehydrogenase activities exhibited significant trend and pairwise comparisons. Although a BMD was estimated for each of these endpoints, these values were much lower (approximately 75- to 230-fold, 140- to 430-fold, and 25- to 80-fold for cholesterol concentration in male rats, aspartate aminotransferase activity in female rats, and sorbitol dehydrogenase activity in female rats, respectively) than would be expected given the endpoint-specific no-observed-effect level (NOEL) and lowest-observed-effect level (LOEL) values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach (Table 4). The BMDs for all clinical pathology endpoints were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values).

Table 4 Summary of Select Clinical Chemistry Data for Male and Female Rats Administered Perfluorohexanesulfonamide for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 9^c^ | 5 | 5 | 5 | 5 | 5 | 5 | 5 | –^d^ | – | NA | NA
Cholesterol (mg/dL) | 103.3 ± 4.4** | 102.2 ± 4.0 | 123.0 ± 12.6 | 115.0 ± 12.1 | 109.2 ± 4.5 | 108.4 ± 6.3 | 90.2 ± 4.8 | 79.8 ± 4.0** | – | – | 0.484^e^ | 0.225^e^
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | – | – | NA | NA
Aspartate Aminotransferase (U/L) | 82.20 ± 1.88** | 80.60 ± 1.21 | 72.40 ± 2.62 | 74.40 ± 3.08 | 77.60 ± 4.50 | 82.00 ± 2.88 | 77.80 ± 4.42 | 69.60 ± 1.57** | – | – | 0.256^e^ | 0.11^e^
Sorbitol Dehydrogenase (IU/L) | 11.9 ± 0.9** | 11.8 ± 0.7 | 9.3 ± 0.5 | 10.1 ± 0.5 | 11.8 ± 1.0 | 11.8 ± 1.5 | 8.6 ± 0.4** | 9.1 ± 0.4* | – | – | 0.455^e^ | 0.264^e^

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose group was not received.

^d^ All male and female 333 and 1,000 mg/kg rats were found dead or moribund and euthanized by study day 1.

^e^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

In male rats, neutrophil count had significant trend and pairwise comparisons. Although a BMD was estimated, its value was much lower (approximately 45- to 140-fold) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach (Table 5). In female rats, there was a negative trend and significant pairwise comparisons for the manual hematocrit in the ≥37 mg/kg groups; a BMD (BMD_L_) was not determined because no viable model was available.

Table 5 Summary of Select Hematology Data for Male and Female Rats Administered Perfluorohexanesulfonamide for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 6^c,d^ | 2^d^ | 4^e^ | 4^e^ | 5 | 3^f^ | 2^d^ | 4^e^ | –^g^ | – | NA | NA
Neutrophils (10^3^/μL) | 0.84 ± 0.12** | 1.08 ± 0.22 | 0.85 ± 0.06 | 1.34 ± 0.16 | 1.54 ± 0.21 | 1.25 ± 0.19 | 1.23 ± 0.01 | 1.24 ± 0.16* | – | – | 0.811^h^ | 0.305^h^
Female
n | 8^f^ | 5 | 5 | 3^f^ | 4^e^ | 4^e^ | 4^e^ | 5 | – | – | NA | NA
Manual Hematocrit (%) | 44.6 ± 0.5** | 47.4 ± 2.7 | 45.0 ± 0.7 | 44.3 ± 0.9 | 44.3 ± 0.5 | 43.5 ± 0.6 | 43.0 ± 0.0* | 42.6 ± 0.7* | – | – | NVM | NVM

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose group was not received.

^d^ Three samples from each of the indicated dose groups had a clot present and were not analyzed.

^e^ One sample from each of the indicated dose groups had a clot present and was not analyzed.

^f^ Two samples from each of the indicated dose groups had a clot present and were not analyzed.

^g^ All male and female 333 and 1,000 mg/kg rats were found dead or moribund and euthanized by study day 1.

^h^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

In male rats, both total thyroxine (total T4) and total triiodothyronine (total T3) concentrations had a negative trend with significant pairwise comparisons in the ≥12 mg/kg and 111 mg/kg groups, respectively (Table 6). The BMDs (BMD_L_s) for decreased total T4 and decreased total T3 were 7.264 (5.024) and 19.107 (7.426) mg/kg, respectively. In female rats, total T4 concentration had significant trend and pairwise comparisons. Although a BMD was estimated, its value was much lower (approximately 30- to 90-fold) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach.

Table 6 Summary of Select Hormone Data for Male and Female Rats Administered Perfluorohexanesulfonamide for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 6^c^ | 3^d^ | 5 | 5 | 4^e^ | 4^e^ | 3^d^ | 5 | –^f^ | – | NA | NA
Total T3 (ng/dL) | 52.550 ± 3.147** | 55.767 ± 8.167 | 58.340 ± 5.567 | 51.040 ± 5.683 | 53.750 ± 5.446 | 49.425 ± 5.193 | 36.467 ± 5.102 | 24.160 ± 1.202** | – | – | 19.107 | 7.426
Total T4 (μg/dL) | 3.03 ± 0.29** | 3.09 ± 0.58 | 2.73 ± 0.27 | 2.69 ± 0.33 | 2.95 ± 0.28 | 2.02 ± 0.34* | 0.79 ± 0.17** | 0.45 ± 0.04** | – | – | 7.264 | 5.024
Female
n | 9^e^ | 4^e^ | 5 | 5 | 4^e^ | 4^e^ | 4^e^ | 5 | – | – | NA | NA
Total T4 (μg/dL) | 2.76 ± 0.15** | 2.74 ± 0.31 | 3.41 ± 0.29 | 3.43 ± 0.24 | 2.62 ± 0.30 | 2.55 ± 0.21 | 1.84 ± 0.23* | 1.06 ± 0.12** | – | – | 0.417^g^ | 0.117^g^

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; total T3 = total triiodothyronine; total T4 = total thyroxine.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Four samples in the indicated dose group did not have sufficient specimen volume available for analysis.

^d^ Two samples in the indicated dose groups did not have sufficient specimen volume available for analysis.

^e^ One sample in the indicated dose groups did not have sufficient specimen volume available for analysis.

^f^ All male and female 333 and 1,000 mg/kg rats were found dead or moribund and euthanized by study day 1.

^g^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

## Internal Dose Assessment

For the 4 and 37 mg/kg groups, PFHxSAm plasma concentrations were determined at 2 and 24 hours following the last dose administered on study day 4 to male and female rats. Average PFHxSAm concentrations are given in Table 7. In general, average plasma concentrations in female rats were higher than those in male rats. At 2 and 24 hours following administration to male and female rats—as the administered dose increased from 4 to 37 mg/kg (a ninefold increase)—there was a less-than-proportional increase (approximately four- and twofold, respectively) in the average PFHxSAm plasma concentration, suggesting changes in the absorption, distribution, metabolism, and excretion processes (e.g., lower absorption and/or induction of metabolism and clearance pathways) as the dose increased. Half-lives estimated using the data from these two time points were longer in female rats (78.2 and 25.6 hours for the 4 and 37 mg/kg groups, respectively) than in male rats (40.1 and 15.1 hours for the 4 and 37 mg/kg groups, respectively). The shorter plasma elimination half-lives estimated for the higher dosed group compared to the lower dosed group suggest induction of clearance pathways as the dose increases.

Table 7 Summary of Plasma Concentration Data for Male and Female Rats Administered Perfluorohexanesulfonamide for Five Days^a^

| 4 mg/kg | 37 mg/kg
n | 3 | 3
Male
2 Hours Postdose (ng/mL) | 33.8 ± 4.43 | 137 ± 10.6
24 Hours Postdose (ng/mL) | 23.1 ± 3.42 | 50.0 ± 19.4
Female
2 Hours Postdose (ng/mL) | 46.3 ± 5.96 | 184 ± 3.06
24 Hours Postdose (ng/mL) | 38.1 ± 3.36 | 101 ± 3.08

If over 20% of the animals in a group are above the limit of detection, then half the limit of detection value is substituted for values that are below it.

^a^ Data are displayed as mean ± standard error of the mean.

## Apical Endpoint Benchmark Dose Summary

A summary of the calculated BMDs for each toxicological endpoint is provided in Table 8. The endpoint-specific LOEL and NOEL are included and could be informative for endpoints that lack a calculated BMD either because no viable model was available or because the estimated BMD was below the lower limit of extrapolation (<0.050 mg/kg).

Table 8 BMD, BMD_L_, LOEL, and NOEL Summary for Apical Endpoints, Sorted by BMD or LOEL from Low to High

Endpoint | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg) | LOEL (mg/kg)^a^ | NOEL (mg/kg) | Direction of Change
Male
Total Thyroxine | 7.264 | 5.024 | 12 | 4 | DOWN
Absolute Liver Weight | 8.492 | 5.426 | 12 | 4 | UP
Relative Liver Weight | 16.251 | 8.358 | 12 | 4 | UP
Total Triiodothyronine | 19.107 | 7.426 | 111 | 37 | DOWN
Cholesterol | UREP^b^ | UREP^b^ | 111 | 37 | –^b^
Neutrophils | UREP | UREP | 111 | 37 | –
Female
Manual Hematocrit | NVM | NVM | 37 | 12 | DOWN
Sorbitol Dehydrogenase | UREP | UREP | 37 | 12 | –
Total Thyroxine | UREP | UREP | 37 | 12 | –
Aspartate Aminotransferase | UREP | UREP | 111 | 37 | –

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; LOEL = lowest-observed-effect level; NOEL = no-observed-effect level; UREP = unreliable estimate of potency is a label based on review by a subject matter expert and rejection of BMD modeling results; NVM = nonviable model, defined as a modeling result that does not meet prespecified fit criteria and hence is deemed unreliable.

^a^ Values in bold text indicate the LOEL of endpoints for which a BMD could not be calculated.

^b^ BMD values are much lower than would be expected given the endpoint-specific LOEL and NOEL values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

## Gene Set Benchmark Dose Analysis

Chemical-induced alterations in liver and kidney gene transcript expression were examined to determine those gene sets most sensitive to PFHxSAm exposure. To that end, BMD analysis of transcripts and gene sets (Gene Ontology [GO] biological process) was conducted to determine the potency of the chemical to elicit gene expression changes in the liver and kidney. This analysis used transcript-level BMD data to assess an aggregate score of gene set potency (median transcript BMD) and enrichment.

The “active” gene sets in the liver and kidney with the lowest BMD median values are shown in Table 9 and Table 10, respectively. The gene sets in Table 9 and Table 10 should be interpreted with caution from the standpoint of the underlying biological mechanism and any relationship to toxicity or toxic agents referenced in the GO term definitions. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes (i.e., a concerted biological change) that could serve as a surrogate of estimated biological potency and, by extension, toxicological potency when more definitive toxicological data are unavailable.

Table 9 Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/ Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0045638 negative regulation of myeloid cell differentiation | 3/31 | 10% | Zfp36; Pik3r1; Nfkbia | 0.520 | 0.160–2.885 | 0 | 3
GO:0001817 regulation of cytokine production | 3/43 | 7% | Zfp36; Hspb1; Egr1 | 0.750 | 0.186–4.702 | 0 | 3
GO:0007611 learning or memory | 4/79 | 5% | Jun; Hmgcr; Fos; Egr1 | 1.190 | 0.425–6.165 | 0 | 4
GO:0030178 negative regulation of Wnt signaling pathway | 3/31 | 10% | Tsku; Foxo3; Egr1 | 1.384 | 0.541–4.702 | 0 | 3
GO:0007612 learning | 3/43 | 7% | Jun; Hmgcr; Fos | 1.631 | 0.663–7.629 | 0 | 3
GO:0006695 cholesterol biosynthetic process | 3/21 | 14% | Tm7sf2; Hsd17b7; Hmgcr | 1.631 | 0.663–7.629 | 0 | 3
GO:0043409 negative regulation of MAPK cascade | 3/51 | 6% | Sirt3; Hmgcr; Dusp6 | 2.380 | 0.663–8.829 | 1 | 2
GO:0014072 response to isoquinoline alkaloid | 3/19 | 16% | Fga; Egr1; Abcg2 | 5.217 | 2.734–11.386 | 1 | 2
GO:0008203 cholesterol metabolic process | 5/49 | 10% | Tm7sf2; Hsd17b7; Hmgcr; Fgl1; Cyp7a1 | 5.721 | 0.985–22.363 | 0 | 5
GO:0051412 response to corticosterone | 3/27 | 11% | Foxo3; Fos; Cdkn1a | 6.250 | 2.440–19.061 | 0 | 3
Female
GO:0018958 phenol-containing compound metabolic process | 4/31 | 13% | Sult1b1; Srd5a1; Dao; Cyp2e1 | 11.677 | 5.931–25.645 | 3 | 1
GO:0046395 carboxylic acid catabolic process | 13/87 | 15% | Gcdh; Ehhadh; Eci2; Eci1; Ech1; Decr1; Dao; Crat; Cpt2; Acox1; Acot4; Acot2; Acaa2 | 12.316 | 8.410–24.399 | 12 | 1
GO:0044242 cellular lipid catabolic process | 13/64 | 20% | Gcdh; Ehhadh; Eci2; Eci1; Ech1; Decr1; Crat; Cpt2; Apoa2; Angptl3; Acox1; Acot2; Acaa2 | 13.636 | 10.423–28.083 | 12 | 1
GO:0009062 fatty acid catabolic process | 11/42 | 26% | Gcdh; Ehhadh; Eci2; Eci1; Ech1; Decr1; Crat; Cpt2; Acox1; Acot2; Acaa2 | 13.636 | 10.423–28.083 | 10 | 1
GO:0044282 small molecule catabolic process | 15/120 | 13% | Sult1e1; Sult1b1; Gcdh; Ehhadh; Eci2; Eci1; Ech1; Decr1; Dao; Crat; Cpt2; Acox1; Acot4; Acot2; Acaa2 | 13.636 | 8.410–28.083 | 14 | 1
GO:0006635 fatty acid beta-oxidation | 10/33 | 30% | Gcdh; Ehhadh; Eci2; Eci1; Ech1; Decr1; Crat; Cpt2; Acox1; Acaa2 | 13.834 | 9.416–29.682 | 9 | 1
GO:0030258 lipid modification | 14/70 | 20% | Pparg; Gcdh; Ephx2; Ehhadh; Eci2; Eci1; Ech1; Decr1; Cyp4a1; Cyp2e1; Crat; Cpt2; Acox1; Acaa2 | 13.834 | 9.416–29.034 | 13 | 1
GO:0017001 antibiotic catabolic process | 3/22 | 14% | Ugt2b1; Sult1e1; Sult1b1 | 15.463 | 7.694–35.088 | 3 | 0
GO:0006805 xenobiotic metabolic process | 9/62 | 15% | Ugt2b1; Sult1b1; Cyp2j4; Cyp2e1; Cyp2d3; Cyp2c24; Cyp2c13; Cyp2c11; Cyp2a1 | 15.463 | 8.238–35.088 | 9 | 0
GO:1901361 organic cyclic compound catabolic process | 6/89 | 7% | Ugt2b1; Sult1e1; Srd5a1; Ephx2; Dao; Akr7a3 | 15.682 | 9.448–32.741 | 5 | 1

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^30^ Official gene symbols from the Rat Genome Database^31^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0045638 negative regulation of myeloid cell differentiation: Any process that stops, prevents, or reduces the frequency, rate, or extent of myeloid cell differentiation.

GO:0001817 regulation of cytokine production: Any process that modulates the frequency, rate, or extent of production of a cytokine.

GO:0007611 learning or memory: The acquisition and processing of information and/or the storage and retrieval of this information over time.

GO:0030178 negative regulation of Wnt signaling pathway: Any process that stops, prevents, or reduces the frequency, rate, or extent of the Wnt signaling pathway.

GO:0007612 learning: Any process in an organism in which a relatively long-lasting adaptive behavioral change occurs as the result of experience.

GO:0006695 cholesterol biosynthetic process: The chemical reactions and pathways resulting in the formation of cholesterol, cholest-5-en-3 beta-ol, the principal sterol of vertebrates and the precursor of many steroids, including bile acids and steroid hormones.

GO:0043409 negative regulation of MAPK cascade: Any process that stops, prevents, or reduces the frequency, rate, or extent of signal transduction mediated by the MAPKKK cascade.

GO:0014072 response to isoquinoline alkaloid: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an isoquinoline alkaloid stimulus. An isoquinoline alkaloid is any member of a group of compounds with the heterocyclic ring structure of benzo(c)pyridine which is a structure characteristic of the group of opium alkaloids.

GO:0008203 cholesterol metabolic process: The chemical reactions and pathways involving cholesterol, cholest-5-en-3 beta-ol, the principal sterol of vertebrates and the precursor of many steroids, including bile acids and steroid hormones. It is a component of the plasma membrane lipid bilayer and of plasma lipoproteins and can be found in all animal tissues.

GO:0051412 response to corticosterone: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a corticosterone stimulus. Corticosterone is a 21-carbon steroid hormone of the corticosteroid type, produced in the cortex of the adrenal glands. In many species, corticosterone is the principal glucocorticoid, involved in regulation of fuel metabolism, immune reactions, and stress responses.

GO:0018958 phenol-containing compound metabolic process: The chemical reactions and pathways involving a phenol, any compound containing one or more hydroxyl groups directly attached to an aromatic carbon ring.

GO:0046395 carboxylic acid catabolic process: The chemical reactions and pathways resulting in the breakdown of carboxylic acids, any organic acid containing one or more carboxyl (-COOH) groups.

GO:0044242 cellular lipid catabolic process: The chemical reactions and pathways resulting in the breakdown of lipids, as carried out by individual cells.

GO:0009062 fatty acid catabolic process: The chemical reactions and pathways resulting in the breakdown of a fatty acid, any of the aliphatic monocarboxylic acids that can be liberated by hydrolysis from naturally occurring fats and oils. Fatty acids are predominantly straight-chain acids of 4 to 24 carbon atoms, which may be saturated or unsaturated; branched fatty acids and hydroxy fatty acids also occur, and very long-chain acids of over 30 carbons are found in waxes.

GO:0044282 small molecule catabolic process: The chemical reactions and pathways resulting in the breakdown of small molecules, any low molecular weight, monomeric, nonencoded molecule.

GO:0006635 fatty acid beta-oxidation: A fatty acid oxidation process that results in the complete oxidation of a long-chain fatty acid. Fatty acid beta-oxidation begins with the addition of coenzyme A to a fatty acid and occurs by successive cycles of reactions during each of which the fatty acid is shortened by a two-carbon fragment removed as acetyl-coenzyme A; the cycle continues until only two or three carbons remain (as acetyl-CoA or propionyl-CoA respectively).

GO:0030258 lipid modification: The covalent alteration of one or more fatty acids in a lipid, resulting in a change in the properties of the lipid.

GO:0017001 antibiotic catabolic process: The chemical reactions and pathways resulting in the breakdown of antibiotic, a substance produced by or derived from certain fungi, bacteria, and other organisms that can destroy or inhibit the growth of other microorganisms.

GO:0006805 xenobiotic metabolic process: The chemical reactions and pathways involving a xenobiotic compound; a compound foreign to the organism exposed to it. It may be synthesized by another organism (like ampicillin) or it can be a synthetic chemical.

GO:1901361 organic cyclic compound catabolic process: The chemical reactions and pathways resulting in the breakdown of organic cyclic compound.

Table 10 Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/ Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0045444 fat cell differentiation | 3/34 | 9% | Srebf1; Pex11a; Cebpd | 8.745 | 5.224–15.487 | 1 | 2
GO:0006984 ER-nucleus signaling pathway | 3/12 | 25% | Srebf1; Insig1; Bcl2l11 | 8.745 | 5.589–15.487 | 2 | 1
GO:0019217 regulation of fatty acid metabolic process | 4/45 | 9% | Srebf1; Ppard; Insig1; Acadl | 9.340 | 5.671–17.150 | 4 | 0
GO:0050796 regulation of insulin secretion | 3/50 | 6% | Srebf1; Ppard; Hadh | 9.934 | 5.754–18.814 | 3 | 0
GO:0051301 cell division | 4/79 | 5% | Top2a; Cenpw; Cdca3; Cdc20 | 10.989 | 7.802–19.064 | 4 | 0
GO:0034329 cell junction assembly | 3/41 | 7% | Lama3; Fgf13; Ect2 | 11.880 | 8.320–21.047 | 2 | 1
GO:0033157 regulation of intracellular protein transport | 6/73 | 8% | Srebf1; Plk3; Kif20b; Insig1; Ect2; C2cd5 | 12.192 | 8.490–21.873 | 4 | 2
GO:0002244 hematopoietic progenitor cell differentiation | 3/31 | 10% | Top2a; Herc6; Cebpd | 12.299 | 8.517–22.796 | 2 | 1
GO:0007059 chromosome segregation | 3/37 | 8% | Top2a; Cenpw; Cenpf | 12.299 | 8.517–22.796 | 3 | 0
GO:0032465 regulation of cytokinesis | 3/28 | 11% | Plk3; Kif20b; Ect2 | 12.504 | 8.661–22.699 | 2 | 1
Female
GO:0051302 regulation of cell division | 3/51 | 6% | Kif18b; Ect2; Aspm | 10.324 | 7.461–16.862 | 3 | 0
GO:0007059 chromosome segregation | 3/37 | 8% | Top2a; Ska1; Kif18b | 11.921 | 8.348–21.048 | 3 | 0
GO:0051301 cell division | 7/79 | 9% | Top2a; Ska1; Kif18b; Cks2; Cdca3; Ccnd1; Aspm | 11.921 | 8.348–21.048 | 7 | 0
GO:0070507 regulation of microtubule cytoskeleton organization | 3/53 | 6% | Ska1; Ckap2; Atf5 | 12.122 | 8.470–21.380 | 2 | 1
GO:0022402 cell cycle process | 10/191 | 5% | Top2a; Kntc1; Kif22; Kif18b; Ect2; Cks2; Ckap2; Cdkn1a; Ccnd1; Aspm | 13.539 | 9.169–26.565 | 9 | 1
GO:1903047 mitotic cell cycle process | 9/146 | 6% | Top2a; Kntc1; Kif22; Kif18b; Ect2; Cks2; Ckap2; Cdkn1a; Ccnd1 | 13.839 | 9.316–27.695 | 8 | 1
GO:1903046 meiotic cell cycle process | 3/29 | 10% | Top2a; Cks2; Aspm | 13.839 | 9.316–27.695 | 3 | 0
GO:0048285 organelle fission | 3/20 | 15% | Top2a; Mx2; Cks2 | 14.420 | 9.624–29.096 | 2 | 1
GO:0033762 response to glucagon | 4/18 | 22% | Srebf1; Pck1; Hmgcs2; Cry1 | 20.917 | 13.412–40.119 | 3 | 1
GO:0032869 cellular response to insulin stimulus | 4/62 | 6% | Srebf1; Pck1; Hmgcs2; Ccl2 | 20.917 | 14.761–40.119 | 3 | 1

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^30^ Official gene symbols from the Rat Genome Database^31^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0045444 fat cell differentiation: The process in which a relatively unspecialized cell acquires specialized features of an adipocyte, an animal connective tissue cell specialized for the synthesis and storage of fat.

GO:0006984 ER-nucleus signaling pathway: Any series of molecular signals that conveys information from the endoplasmic reticulum to the nucleus, usually resulting in a change in transcriptional regulation.

GO:0019217 regulation of fatty acid metabolic process: Any process that modulates the frequency, rate, or extent of the chemical reactions and pathways involving fatty acids.

GO:0050796 regulation of insulin secretion: Any process that modulates the frequency, rate, or extent of the regulated release of insulin.

GO:0051301 cell division: The process resulting in division and partitioning of components of a cell to form more cells; may or may not be accompanied by the physical separation of a cell into distinct, individually membrane-bounded daughter cells.

GO:0034329 cell junction assembly: A cellular process that results in the aggregation, arrangement, and bonding together of a set of components to form a cell junction.

GO:0033157 regulation of intracellular protein transport: Any process that modulates the frequency, rate, or extent of the directed movement of proteins within cells.

GO:0002244 hematopoietic progenitor cell differentiation: The process in which precursor cell type acquires the specialized features of a hematopoietic progenitor cell, a class of cell types including myeloid progenitor cells and lymphoid progenitor cells.

GO:0007059 chromosome segregation: The process in which genetic material, in the form of chromosomes, is organized into specific structures and then physically separated and apportioned to two or more sets. In eukaryotes, chromosome segregation begins with the condensation of chromosomes, includes chromosome separation, and ends when chromosomes have completed movement to the spindle poles.

GO:0032465 regulation of cytokinesis: Any process that modulates the frequency, rate, or extent of the division of the cytoplasm of a cell and its separation into two daughter cells.

GO:0051302 regulation of cell division: Any process that modulates the frequency, rate, or extent of the physical partitioning and separation of a cell into daughter cells.

GO:0070507 regulation of microtubule cytoskeleton organization: Any process that modulates the frequency, rate, or extent of the formation, arrangement of constituent parts, or disassembly of cytoskeletal structures comprising microtubules and their associated proteins.

GO:0022402 cell cycle process: The cellular process that ensures successive accurate and complete genome replication and chromosome segregation.

GO:1903047 mitotic cell cycle process: A process that is part of the mitotic cell cycle.

GO:1903046 meiotic cell cycle process: A process that is part of the meiotic cell cycle.

GO:0048285 organelle fission: The creation of two or more organelles by division of one organelle.

GO:0033762 response to glucagon: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a glucagon stimulus.

GO:0032869 cellular response to insulin stimulus: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an insulin stimulus. Insulin is a polypeptide hormone produced by the islets of Langerhans of the pancreas in mammals and by the homologous organs of other organisms.

No gene sets in the liver of male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were negative regulation of myeloid cell differentiation (GO:0045638) and regulation of cytokine production (GO:0001817) with median BMDs (BMD_L_s) of 0.520 (0.160) and 0.750 (0.186) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were phenol-containing compound metabolic process (GO:0018958) and carboxylic acid catabolic process (GO:0046395) with median BMDs (BMD_L_s) of 11.677 (5.931) and 12.316 (8.410) mg/kg, respectively.

No gene sets in the kidney of male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were fat cell differentiation (GO:0045444) and ER-nucleus signaling pathway (GO:0006984) with median BMDs (BMD_L_s) of 8.745 (5.224) and 8.745 (5.589) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were regulation of cell division (GO:0051302) with a median BMD (BMD_L_) of 10.324 (7.461) mg/kg, and chromosome segregation (GO:0007059) and cell division (GO: 0051301), both with a median BMD (BMD_L_) of 11.921 (8.348) mg/kg. The full list of affected gene sets in the liver and kidney of male and female rats can be found in Appendix F.

## Gene Benchmark Dose Analysis

The top 10 genes based on BMD potency in the liver and kidney (fold change >|2|, significant Williams trend test, global goodness-of-fit p value >0.1, and BMD_U_/BMD_L_ ≤40) are shown in Table 11 and Table 12. As with the GO analysis, the biological or toxicological significance of the changes in gene expression shown in Table 11 and Table 12 should be interpreted with caution. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes that could serve as a conservative surrogate of estimated biological potency, and by extension toxicological potency, when more definitive toxicological data are unavailable.

Table 11 Top 10 Liver Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Egr1 | 24330 | EGR1_8533 | | 0.750 (0.186–4.702) | 4.2 | DOWN
Zfp354a | 24522 | ZFP354A_10203 | | 0.835 (0.271–2.999) | 4.6 | DOWN
Tsku | 308843 | TSKU_10094 | | 1.384 (0.541–4.109) | 3.0 | DOWN
Cyp7a1 | 25428 | CYP7A1_8430 | | 5.721 (0.985–22.363) | 4.6 | DOWN
Gsta2 | 24422 | GSTA2_8756 | | 5.725 (1.686–19.439) | 2.3 | UP
Gsta5 | 494499 | GSTA2_8756 | | 5.725 (1.686–19.439) | 2.3 | UP
Crot | 83842 | CROT_8384 | | 7.423 (5.757–10.316) | 6.0 | UP
Slc27a2 | 65192 | SLC27A2_9860 | | 7.622 (5.499–13.393) | 2.2 | UP
Acaa1a | 24157 | ACAA1A_7954 | | 8.417 (7.129–10.157) | 13.3 | UP
Acaa1b | 501072 | ACAA1A_7954 | | 8.417 (7.129–10.157) | 13.3 | UP
Female
A2m | 24153 | A2M_7932 | 1.163 (0.179–7.061) | | 2.3 | DOWN
Loc100911545/A2m | 100911545 | A2M_7932 | 1.163 (0.179–7.061) | | 2.3 | DOWN
Dao | 114027 | DAO_8437 | 6.134 (2.436–16.203) | | 2.1 | UP
Ephx2 | 65030 | EPHX2_33282 | 6.441 (2.664–17.347) | | 2.4 | UP
Ehhadh | 171142 | EHHADH_8534 | 7.300 (5.266–11.878) | | 4.0 | UP
Cyp2b1 | 24300 | CYP2B1_32451 | 7.456 (5.106–13.104) | | 31.5 | UP
Loc108348266/Cyp2b1 | 108348266 | CYP2B1_32451 | 7.456 (5.106–13.104) | | 31.5 | UP
Cyp2c6v1 | 293989 | CYP2C6V1_33169 | 9.829 (7.252–14.982) | | 2.4 | UP
Loc100911718 | 100911718 | CYP2C6V1_33169 | 9.829 (7.252–14.982) | | 2.4 | UP
Ech1 | 64526 | ECH1_8516 | 9.874 (6.591–19.440) | | 3.6 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^32^ and Entrez Gene.^33^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Egr1: Human Uniprot function (Human EGR1): Transcriptional regulator (PubMed20121949). Recognizes and binds to the DNA sequence 5’-GCG(T/G)GGGCG-3’(EGR-site) in the promoter region of target genes (by similarity). Binds double-stranded target DNA, irrespective of the cytosine methylation status (PubMed25258363, PubMed25999311). Regulates the transcription of numerous target genes, and thereby plays an important role in regulating the response to growth factors, DNA damage, and ischemia. Plays a role in the regulation of cell survival, proliferation, and cell death. Activates expression of p53/TP53 and TGFB1, and thereby helps prevent tumor formation. Required for normal progress through mitosis and normal proliferation of hepatocytes after partial hepatectomy. Mediates responses to ischemia and hypoxia; regulates the expression of proteins such as IL1B and CXCL2 that are involved in inflammatory processes and development of tissue damage after ischemia. Regulates biosynthesis of luteinizing hormone (LHB) in the pituitary (by similarity). Regulates the amplitude of the expression rhythms of clock genes ARNTL/BMAL1, PER2 and NR1D1 in the liver via the activation of PER1 (clock repressor) transcription. Regulates the rhythmic expression of core-clock gene ARNTL/BMAL1 in the suprachiasmatic nucleus (SCN) (by similarity). {ECO0000250|UniProtKBP08046, ECO0000269|PubMed20121949, ECO0000269|PubMed25258363, ECO0000269|PubMed25999311}.

Zfp354a: Rat Uniprot Function (Human ZNF354A): It may play a role in renal development and may also be involved in the repair of the kidney after ischemia-reperfusion or folic acid administration.

Tsku: Human Uniprot function (Human TSKU): Contributes to various developmental events and other processes such as wound healing and cholesterol homeostasis through its interactions with multiple signaling pathways. Wnt signaling inhibitor which competes with WNT2B for binding to Wnt receptor FZD4 and represses WNT2B-dependent development of the peripheral eye. Plays a role in regulating the hair cycle by controlling TGFB1 signaling. Required for the development of the anterior commissure in the brain by inhibiting neurite outgrowth. Essential for terminal differentiation of hippocampal neural stem cells. Plays a role in regulating bone elongation and bone mass by modulating growth plate chondrocyte function and overall body size. Required for development of the inner ear through its involvement in stereocilia formation in inner hair cells. Facilitates wound healing by inhibiting secretion of TGFB1 from macrophages which prevents myofibroblast differentiation, maintaining inflammatory cell quiescence. Plays a role in cholesterol homeostasis by reducing circulating high-density lipoprotein cholesterol, lowering cholesterol efflux capacity and decreasing cholesterol-to-bile acid conversion in the liver. In one study, shown to negatively regulate sympathetic innervation in brown fat, leading to reduced energy expenditure. In another study, shown not to affect brown fat thermogenic capacity, body weight gain or glucose homeostasis.

Cyp7a1: Human Uniprot function (Human CYP7A1): A cytochrome P450 monooxygenase involved in the metabolism of endogenous cholesterol and its oxygenated derivatives (oxysterols) (PubMed11013305, PubMed12077124, PubMed19965590, PubMed2384150, PubMed21813643). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (CPR; NADPH-ferrihemoprotein reductase) (PubMed2384150, PubMed11013305, PubMed12077124, PubMed19965590, PubMed21813643). Functions as a critical regulatory enzyme of bile acid biosynthesis and cholesterol homeostasis. Catalyzes the hydroxylation of carbon-hydrogen bond at 7-alpha position of cholesterol, a rate-limiting step in cholesterol catabolism and bile acid biosynthesis (PubMed12077124, PubMed19965590, PubMed2384150). 7-alpha hydroxylates several oxysterols, including 4beta-hydroxycholesterol and 24-hydroxycholesterol (PubMed11013305, PubMed12077124). Catalyzes the oxidation of the 7,8 double bond of 7-dehydrocholesterol and lathosterol with direct and predominant formation of the 7-keto derivatives (PubMed21813643). {ECO0000269|PubMed11013305, ECO0000269|PubMed12077124, ECO0000269|PubMed19965590, ECO0000269|PubMed21813643, ECO0000269|PubMed2384150}.

Gsta2: Human Uniprot function (Human GSTA2): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles.

Gsta5: Rat Uniprot Function (Human GSTA5): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles. Has substantial activity toward aflatoxin B1-8,9-epoxide.

Crot: Human Uniprot function (Human CROT): Beta-oxidation of fatty acids. The highest activity concerns the C6 to C10 chain length substrate. Converts the end product of pristanic acid beta-oxidation, 4,8-dimethylnonanoyl-CoA, to its corresponding carnitine ester. {ECO0000269|PubMed10486279}.

Slc27a2: Human Uniprot function (Human SLC27A2): Acyl-CoA synthetase that activates long-chain and very long-chain fatty acids (VLCFAs) by catalyzing the formation of fatty acyl-CoA (PubMed10198260, PubMed10749848, PubMed11980911). Can also activate branched-chain fatty acids such as phytanic acid and pristanic acid (PubMed10198260). Does not activate C24 bile acids, cholate and chenodeoxycholate (PubMed11980911). In vitro, activates 3-alpha,7-alpha,12-alpha-trihydroxy-5-beta-cholestanate (THCA), the C27 precursor of cholic acid deriving from the de novo synthesis from cholesterol (PubMed11980911). Exhibits long-chain fatty acids (LCFA) transport activity and plays an important role in hepatic fatty acid uptake (PubMed20530735). {ECO0000269|PubMed10198260, ECO0000269|PubMed10749848, ECO0000269|PubMed11980911, ECO0000269|PubMed20530735}. FUNCTION [Isoform 1] Exhibits both long-chain fatty acids (LCFA) transport activity and acyl-CoA synthetase toward very long-chain fatty acids (PubMed21768100). Shows a preference for generating CoA derivatives of n-3 fatty acids, which are preferentially trafficked into phosphatidylinositol (PubMed21768100). {ECO0000269|PubMed21768100}. FUNCTION [Isoform 2] Exhibits long-chain fatty acids (LCFA) transport activity but lacks acyl-CoA synthetase toward very long-chain fatty acids. {ECO0000269|PubMed21768100}.

Acaa1a: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. [provided by RefSeq, Jul 2008]

Acaa1b: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. [provided by RefSeq, Jul 2008]

A2m: Human Uniprot function (Human A2M): Is able to inhibit all four classes of proteinases by a unique ‘trapping’ mechanism. This protein has a peptide stretch, called the ‘bait region’ which contains specific cleavage sites for different proteinases. When a proteinase cleaves the bait region, a conformational change is induced in the protein which traps the proteinase. The entrapped enzyme remains active against low molecular weight substrates (activity against high molecular weight substrates is greatly reduced). Following cleavage in the bait region, a thioester bond is hydrolyzed and mediates the covalent binding of the protein to the proteinase.

LOC100911545/A2m: Human Uniprot function (Human A2M): Is able to inhibit all four classes of proteinases by a unique ‘trapping’ mechanism. This protein has a peptide stretch, called the ‘bait region’ which contains specific cleavage sites for different proteinases. When a proteinase cleaves the bait region, a conformational change is induced in the protein which traps the proteinase. The entrapped enzyme remains active against low molecular weight substrates (activity against high molecular weight substrates is greatly reduced). Following cleavage in the bait region, a thioester bond is hydrolyzed and mediates the covalent binding of the protein to the proteinase.

Dao: Human Uniprot function (Human DAO): Regulates the level of the neuromodulator D-serine in the brain. Has high activity toward D-DOPA and contributes to dopamine synthesis. Could act as a detoxifying agent which removes D-amino acids accumulated during aging. Acts on a variety of D-amino acids with a preference for those having small hydrophobic side chains followed by those bearing polar, aromatic, and basic groups. Does not act on acidic amino acids. {ECO0000269|PubMed17303072}.

Ephx2: Human Uniprot function (Human EPHX2): Bifunctional enzyme (PubMed12574510). The C-terminal domain has epoxide hydrolase activity and acts on epoxides (alkene oxides, oxiranes) and arene oxides (PubMed12869654, PubMed12574510, PubMed22798687). Plays a role in xenobiotic metabolism by degrading potentially toxic epoxides (by similarity). Also determines steady-state levels of physiological mediators (PubMed12869654, PubMed12574510, PubMed22798687, PubMed21217101). {ECO0000250|UniProtKBP80299, ECO0000269|PubMed12574508, ECO0000269|PubMed12574510, ECO0000269|PubMed12869654, ECO0000269|PubMed21217101, ECO0000269|PubMed22798687}. FUNCTION Bifunctional enzyme (PubMed12574510). The N-terminal domain has lipid phosphatase activity, with the highest activity toward threo-9,10-phosphonooxy-hydroxy-octadecanoic acid, followed by erythro-9,10-phosphonooxy-hydroxy-octadecanoic acid, 12-phosphonooxy-octadec-9Z-enoic acid and 12-phosphonooxy-octadec-9E-enoic acid (PubMed12574510). Has phosphatase activity toward lyso-glycerophospholipids with also some lower activity toward lysolipids of sphingolipid and isoprenoid phosphates (PubMed22217705, PubMed22387545). {ECO0000269|PubMed12574510, ECO0000269|PubMed22217705, ECO0000269|PubMed22387545}.

Ehhadh: Human Uniprot function (Human EHHADH): Peroxisomal trifunctional enzyme possessing 2-enoyl-CoA hydratase, 3-hydroxyacyl-CoA dehydrogenase, and delta 3, delta 2-enoyl-CoA isomerase activities. Catalyzes two of the four reactions of the long straight-chain fatty acids peroxisomal beta-oxidation pathway. Optimal isomerase for 2,5 double bonds into 3,5 form isomerization in a range of enoyl-CoA species (probable). Also able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species (by similarity). With HSD17B4, catalyzes the hydration of trans-2-enoyl-CoA and the dehydrogenation of 3-hydroxyacyl-CoA, but with opposite chiral specificity (PubMed15060085). Regulates the amount of medium-chain dicarboxylic fatty acids which are essential regulators of all fatty acid oxidation pathways (by similarity). Also involved in the degradation of long-chain dicarboxylic acids through peroxisomal beta-oxidation (PubMed15060085). {ECO0000250|UniProtKBP07896, ECO0000250|UniProtKBQ9DBM2, ECO0000269|PubMed15060085, ECO0000305|PubMed15060085}.

Cyp2b1: Human Uniprot function (Human CYP2B6): A cytochrome P450 monooxygenase involved in the metabolism of endocannabinoids and steroids (PubMed21289075, PubMed12865317). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH--hemoprotein reductase). Catalyzes the epoxidation of double bonds of arachidonoylethanolamide (anandamide) to 8,9-, 11,12-, and 14,15-epoxyeicosatrienoic acid ethanolamides (EpETrE-Eas), potentially modulating endocannabinoid system signaling (PubMed21289075). Hydroxylates steroid hormones, including testosterone at C-16 and estrogens at C-2 (PubMed21289075, PubMed12865317). Plays a role in the oxidative metabolism of xenobiotics, including plant lipids and drugs (PubMed11695850, PubMed22909231). Acts as a 1,4-cineole 2-exo-monooxygenase (PubMed11695850). {ECO0000269|PubMed11695850, ECO0000269|PubMed12865317, ECO0000269|PubMed21289075, ECO0000269|PubMed22909231}. FUNCTION Allele 2B6*9 Has low affinity for anandamide and can only produce 11,12 EpETrE-Eas. {ECO0000269|PubMed21289075}.

LOC108348266/Cyp2b1: Human Uniprot function (Human CYP2B6): A cytochrome P450 monooxygenase involved in the metabolism of endocannabinoids and steroids (PubMed21289075, PubMed12865317). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH--hemoprotein reductase). Catalyzes the epoxidation of double bonds of arachidonoylethanolamide (anandamide) to 8,9-, 11,12-, and 14,15-epoxyeicosatrienoic acid ethanolamides (EpETrE-Eas), potentially modulating endocannabinoid system signaling (PubMed21289075). Hydroxylates steroid hormones, including testosterone at C-16 and estrogens at C-2 (PubMed21289075, PubMed12865317). Plays a role in the oxidative metabolism of xenobiotics, including plant lipids and drugs (PubMed11695850, PubMed22909231). Acts as a 1,4-cineole 2-exo-monooxygenase (PubMed11695850).

Cyp2c6v1: Human Uniprot function (Human CYP2C19): A cytochrome P450 monooxygenase involved in the metabolism of polyunsaturated fatty acids (PUFA) (PubMed18577768, PubMed19965576, PubMed20972997). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH--hemoprotein reductase) (PubMed18577768, PubMed19965576, PubMed20972997). Catalyzes the hydroxylation of carbon-hydrogen bonds. Hydroxylates PUFA specifically at the omega-1 position (PubMed18577768). Catalyzes the epoxidation of double bonds of PUFA (PubMed20972997, PubMed19965576). Also metabolizes plant monoterpenes such as limonene. Oxygenates (R)- and (S)-limonene to produce carveol and perillyl alcohol (PubMed11950794). Responsible for the metabolism of a number of therapeutic agents such as the anticonvulsant drug S-mephenytoin, omeprazole, proguanil, certain barbiturates, diazepam, propranolol, citalopram, and imipramine. Hydroxylates fenbendazole at the 4’ position (PubMed23959307). {ECO0000269|PubMed11950794, ECO0000269|PubMed18577768, ECO0000269|PubMed19965576, ECO0000269|PubMed20972997, ECO0000269|PubMed23959307}.

LOC100911718: Human Uniprot function (Human CYP2C18): A cytochrome P450 monooxygenase involved in retinoid metabolism. Hydroxylates all trans-retinoic acid (atRA) to 4-hydroxyretinoate and may modulate atRA signaling and clearance. Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (CPR; NADPH-ferrihemoprotein reductase). CP2CI_HUMAN,P33260

Ech1: Human Uniprot function (Human ECH1): Isomerization of 3-trans,5-cis-dienoyl-CoA to 2-trans,4-trans-dienoyl-CoA. {ECO0000250|UniProtKBQ62651}.

Table 12 Top 10 Kidney Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Loc100911814/Spink1l | 100911814 | LOC100911814_9091 | 0.510 (0.212–1.639) | 3.0 | DOWN
Insig1 | 64194 | INSIG1_8906 | 7.612 (5.589–12.856) | 3.8 | UP
Srebf1 | 78968 | SREBF1_32750 | 8.745 (5.224–15.487) | 3.8 | UP
Fads1 | 84575 | FADS1_8593 | 9.357 (6.123–15.758) | 2.4 | UP
Ppard | 25682 | PPARD_9536 | 9.934 (5.754–18.814) | 2.4 | UP
Decr1 | 117543 | DECR1_8458 | 12.862 (10.721–15.913) | 2.2 | UP
Acot2 | 192272 | ACOT2_7969 | 13.201 (10.994–16.357) | 2.3 | UP
Acaa1a | 24157 | ACAA1A_7954 | 13.398 (11.228–16.447) | 3.9 | UP
Acaa1b | 501072 | ACAA1A_7954 | 13.398 (11.228–16.447) | 3.9 | UP
Fasn | 50671 | FASN_8611 | 13.486 (11.223–16.732) | 2.3 | UP
Female
Cdca3 | 297594 | CDCA3_8260 | 2.619 (0.978–7.970) | 2.3 | UP
Pck1 | 362282 | PCK1_9439 | 5.515 (1.341–39.672) | 2.3 | UP
Slc10a1 | 24777 | SLC10A1_9832 | 7.968 (6.075–11.486) | 2.5 | DOWN
Cyp2c24 | 499353 | CYP2C24_32875 | 10.565 (7.636–17.047) | 2.3 | DOWN
Ube2t | 360847 | UBE2T_10125 | 10.991 (7.866–18.206) | 2.4 | UP
Srebf1 | 78968 | SREBF1_32750 | 11.236 (4.944–24.577) | 2.9 | UP
Ckap2 | 306575 | CKAP2_8324 | 12.122 (8.470–21.380) | 2.2 | UP
Lilra3 | 100912499 | LILRA3_32676 | 17.020 (10.650–96.524) | 2.5 | UP
Lilrb3l | 361493 | LILRA3_32676 | 17.020 (10.650–96.524) | 2.5 | UP
Acaa1a | 24157 | ACAA1A_7954 | 17.682 (14.617–22.195) | 2.2 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^32^ and Entrez Gene.^33^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

LOC100911814/Spink1l: Human Uniprot function (Human GLDC): The glycine cleavage system catalyzes the degradation of glycine. The P protein (GLDC) binds the alpha-amino group of glycine through its pyridoxal phosphate cofactor; CO(2) is released, and the remaining methylamine moiety is then transferred to the lipoamide cofactor of the H protein (GCSH).

Insig1: Human Uniprot function (Human INSIG1): Oxysterol-binding protein that mediates feedback control of cholesterol synthesis by controlling both endoplasmic reticulum to Golgi transport of SCAP and degradation of HMGCR (PubMed12202038, PubMed12535518, PubMed16168377, PubMed16399501, PubMed16606821, PubMed32322062). Acts as a negative regulator of cholesterol biosynthesis by mediating the retention of the SCAP-SREBP complex in the endoplasmic reticulum, thereby blocking the processing of sterol regulatory element-binding proteins (SREBPs) SREBF1/SREBP1 and SREBF2/SREBP2 (PubMed12202038, PubMed16399501, PubMed32322062). Binds oxysterol, including 25-hydroxycholesterol, regulating interaction with SCAP and retention of the SCAP-SREBP complex in the endoplasmic reticulum (PubMed32322062). In the presence of oxysterol, it interacts with SCAP, retaining the SCAP-SREBP complex in the endoplasmic reticulum, thereby preventing SCAP from escorting SREBF1/SREBP1 and SREBF2/SREBP2 to the Golgi (PubMed15899885, PubMed32322062). Sterol deprivation or phosphorylation by PCK1 reduce oxysterol-binding, disrupting the interaction between INSIG1 and SCAP, thereby promoting Golgi transport of the SCAP-SREBP complex, followed by processing and nuclear translocation of SREBF1/SREBP1 and SREBF2/SREBP2 (PubMed32322062). Also regulates cholesterol synthesis by regulating degradation of HMGCR initiates the sterol-mediated ubiquitin-mediated endoplasmic reticulum-associated degradation (ERAD) of HMGCR via recruitment of the reductase to the ubiquitin ligases AMFR/gp78 and/or RNF139 (PubMed12535518, PubMed16168377, PubMed22143767). Also regulates degradation of SOAT2/ACAT2 when the lipid levels are low; initiates the ubiquitin-mediated degradation of SOAT2/ACAT2 via recruitment of the ubiquitin ligases AMFR/gp78 (PubMed28604676). {ECO0000269|PubMed12202038, ECO0000269|PubMed12535518, ECO0000269|PubMed15899885, ECO0000269|PubMed16168377, ECO0000269|PubMed16399501, ECO0000269|PubMed16606821, ECO0000269|PubMed22143767, ECO0000269|PubMed28604676, ECO0000269|PubMed32322062}.

Srebf1: Human Uniprot function (Human SREBF1): [Sterol regulatory element-binding protein 1] Precursor of the transcription factor form (Processed sterol regulatory element-binding protein 1), which is embedded in the endoplasmic reticulum membrane (PubMed32322062). Low sterol concentrations promote processing of this form, releasing the transcription factor form that translocates into the nucleus and activates transcription of genes involved in cholesterol biosynthesis and lipid homeostasis (by similarity). {ECO0000250|UniProtKBQ9WTN3, ECO0000269|PubMed32322062}. FUNCTION [Processed sterol regulatory element-binding protein 1] Key transcription factor that regulates expression of genes involved in cholesterol biosynthesis and lipid homeostasis (PubMed8402897, PubMed12177166, PubMed32322062). Binds to the sterol regulatory element 1 (SRE-1) (5’-ATCACCCCAC-3’). Has dual sequence specificity binding to both an E-box motif (5’-ATCACGTGA-3’) and to SRE-1 (5’-ATCACCCCAC-3’) (PubMed8402897, PubMed12177166). Regulates the promoters of genes involved in cholesterol biosynthesis and the LDL receptor (LDLR) pathway of sterol regulation (PubMed8402897, PubMed12177166, PubMed32322062). {ECO0000269|PubMed12177166, ECO0000269|PubMed32322062, ECO0000269|PubMed8402897}. FUNCTION [Isoform SREBP-1A] Isoform expressed only in select tissues, which has higher transcriptional activity compared to SREBP-1C (by similarity). Able to stimulate both lipogenic and cholesterogenic gene expression (PubMed12177166). Has a role in the nutritional regulation of fatty acids and triglycerides in lipogenic organs such as the liver (by similarity). Required for innate immune response in macrophages by regulating lipid metabolism (by similarity). {ECO0000250|UniProtKBQ9WTN3, ECO0000269|PubMed12177166}. FUNCTION [Isoform SREBP-1C] Predominant isoform expressed in most tissues, which has weaker transcriptional activity compared to isoform SREBP-1A (by similarity). Primarily controls expression of lipogenic gene (PubMed12177166). Strongly activates global lipid synthesis in rapidly growing cells (by similarity). {ECO0000250|UniProtKBQ9WTN3, ECO0000269|PubMed12177166}. FUNCTION [Isoform SREBP-1aDelta] The absence of Golgi proteolytic processing requirement makes this isoform constitutively active in transactivation of lipogenic gene promoters. {ECO0000305|PubMed7759101}. FUNCTION [Isoform SREBP-1cDelta] The absence of Golgi proteolytic processing requirement makes this isoform constitutively active in transactivation of lipogenic gene promoters. {ECO0000305|PubMed7759101}.

Fads1: Human Uniprot function (Human FADS1): [Isoform 1] Acts as a front-end fatty acyl-coenzyme A (CoA) desaturase that introduces a cis double bond at carbon 5 located between a preexisting double bond and the carboxyl end of the fatty acyl chain. Involved in biosynthesis of highly unsaturated fatty acids (HUFA) from the essential polyunsaturated fatty acids (PUFA) linoleic acid (LA) (182n-6) and alpha-linolenic acid (ALA) (183n-3) precursors. Specifically, desaturates dihomo-gamma-linoleoate (DGLA) (203n-6) and eicosatetraenoate (ETA) (204n-3) to generate arachidonate (AA) (204n-6) and eicosapentaenoate (EPA) (205n-3), respectively (PubMed10601301, PubMed10769175). As a rate-limiting enzyme for DGLA (203n-6) and AA (204n-6)-derived eicosanoid biosynthesis, controls the metabolism of inflammatory lipids like prostaglandin E2, critical for efficient acute inflammatory response and maintenance of epithelium homeostasis. Contributes to membrane phospholipid biosynthesis by providing AA (204n-6) as a major acyl chain esterified into phospholipids. In particular, regulates phosphatidylinositol-4,5-bisphosphate levels, modulating inflammatory cytokine production in T-cells (by similarity). Also desaturates (11E)-octadecenoate (trans-vaccenoate)(181n-9), a metabolite in the biohydrogenation pathway of LA (182n-6) (by similarity). {ECO0000250|UniProtKBQ920L1, ECO0000250|UniProtKBQ920R3, ECO0000269|PubMed10601301, ECO0000269|PubMed10769175}. FUNCTION [Isoform 2] Does not exhibit any catalytic activity toward 203n-6, but it may enhance FADS2 activity. {ECO0000250|UniProtKBA4UVI1}.

Ppard: Human Uniprot function (Human PPARD): Ligand-activated transcription factor. Receptor that binds peroxisome proliferators such as hypolipidemic drugs and fatty acids. Has a preference for polyunsaturated fatty acids, such as gamma-linoleic acid and eicosapentanoic acid. Once activated by a ligand, the receptor binds to promoter elements of target genes. Regulates the peroxisomal beta-oxidation pathway of fatty acids. Functions as transcription activator for the acyl-CoA oxidase gene. Decreases expression of NPC1L1 once activated by a ligand. {ECO0000269|PubMed1333051, ECO0000269|PubMed15604518}.

Decr1: Human Uniprot function (Human DECR1): Auxiliary enzyme of beta-oxidation. It participates in the metabolism of unsaturated fatty enoyl-CoA esters having double bonds in both even- and odd-numbered positions in mitochondria. Catalyzes the NADP-dependent reduction of 2,4-dienoyl-CoA to yield trans-3-enoyl-CoA. {ECO0000269|PubMed15531764}.

Acot2: Human Uniprot function (Human ACOT2): Acyl-CoA thioesterases are a group of enzymes that catalyze the hydrolysis of acyl-CoAs to the free fatty acid and coenzyme A (CoASH), providing the potential to regulate intracellular levels of acyl-CoAs, free fatty acids and CoASH (PubMed16940157). Acyl-coenzyme A thioesterase 2/ACOT2 displays higher activity toward long-chain acyl-CoAs (C14-C20) (PubMed16940157, PubMed10944470). The enzyme is involved in enhancing the hepatic fatty acid oxidation in mitochondria (by similarity). {ECO0000250|UniProtKBQ9QYR9, ECO0000269|PubMed10944470, ECO0000269|PubMed16940157, ECO0000303|PubMed16940157}.

Acaa1a: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. [provided by RefSeq, Jul 2008]

Acaa1b: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. [provided by RefSeq, Jul 2008]

Fasn: Human Uniprot function (Human FASN): Fatty acid synthetase is a multifunctional enzyme that catalyzes the de novo biosynthesis of long-chain saturated fatty acids starting from acetyl-CoA and malonyl-CoA in the presence of NADPH. This multifunctional protein contains seven catalytic activities and a site for the binding of the prosthetic group 4’-phosphopantetheine of the acyl carrier protein (ACP) domain. {ECO0000269|PubMed16215233, ECO0000269|PubMed16969344, ECO0000269|PubMed26851298, ECO0000269|PubMed7567999, ECO0000269|PubMed8962082, ECO0000269|PubMed9356448}.

Cdca3: Human Uniprot function (Human CDCA3): F-box-like protein that is required for entry into mitosis. Acts by participating in E3 ligase complexes that mediate the ubiquitination and degradation of WEE1 kinase at G2/M phase (by similarity). {ECO0000250}.

Pck1: Human Uniprot function (Human PCK1): Cytosolic phosphoenolpyruvate carboxykinase that catalyzes the reversible decarboxylation and phosphorylation of oxaloacetate (OAA) and acts as the rate-limiting enzyme in gluconeogenesis (PubMed30193097, PubMed24863970, PubMed26971250, PubMed28216384). Regulates cataplerosis and anaplerosis, the processes that control the levels of metabolic intermediates in the citric acid cycle (PubMed30193097, PubMed24863970, PubMed26971250, PubMed28216384). At low glucose levels, it catalyzes the cataplerotic conversion of oxaloacetate to phosphoenolpyruvate (PEP), the rate-limiting step in the metabolic pathway that produces glucose from lactate and other precursors derived from the citric acid cycle (PubMed30193097). At high glucose levels, it catalyzes the anaplerotic conversion of phosphoenolpyruvate to oxaloacetate (PubMed30193097). Acts as a regulator of formation and maintenance of memory CD8(+) T-cells upregulated in these cells, where it generates phosphoenolpyruvate, via gluconeogenesis (by similarity). The resultant phosphoenolpyruvate flows to glycogen and pentose phosphate pathway, which is essential for memory CD8(+) T-cells homeostasis (by similarity). In addition to the phosphoenolpyruvate carboxykinase activity, also acts as a protein kinase when phosphorylated at Ser-90 phosphorylation at Ser-90 by AKT1 reduces the binding affinity to oxaloacetate and promotes an atypical serine protein kinase activity using GTP as donor (PubMed32322062). The protein kinase activity regulates lipogenesis upon phosphorylation at Ser-90, translocates to the endoplasmic reticulum and catalyzes phosphorylation of INSIG proteins (INSIG1 and INSIG2), thereby disrupting the interaction between INSIG proteins and SCAP and promoting nuclear translocation of SREBP proteins (SREBF1/SREBP1 or SREBF2/SREBP2) and subsequent transcription of downstream lipogenesis-related genes (PubMed32322062). {ECO0000250|UniProtKBQ9Z2V4, ECO0000269|PubMed24863970, ECO0000269|PubMed26971250, ECO0000269|PubMed28216384, ECO0000269|PubMed30193097, ECO0000269|PubMed32322062}.

Slc10a1: Human Uniprot function (Human SLC10A1): The hepatic sodium/bile acid uptake system exhibits broad substrate specificity and transports various non-bile acid organic compounds as well. It is strictly dependent on the extracellular presence of sodium. FUNCTION (Microbial infection) Acts as a receptor for hepatitis B virus. {ECO0000269|PubMed23150796}.

Cyp2c24: Human Uniprot function (Human CYP2C18): Cytochromes P450 are a group of heme-thiolate monooxygenases. In liver microsomes, this enzyme is involved in an NADPH-dependent electron transport pathway. It oxidizes a variety of structurally unrelated compounds, including steroids, fatty acids, and xenobiotics.

Ube2t: Human Uniprot function (Human UBE2T): Accepts ubiquitin from the E1 complex and catalyzes its covalent attachment to other proteins. Catalyzes monoubiquitination. Involved in mitomycin-C (MMC)-induced DNA repair. Acts as a specific E2 ubiquitin-conjugating enzyme for the Fanconi anemia complex by associating with E3 ubiquitin-protein ligase FANCL and catalyzing monoubiquitination of FANCD2, a key step in the DNA damage pathway (PubMed16916645, PubMed17938197, PubMed19111657, PubMed19589784, PubMed28437106). Also mediates monoubiquitination of FANCL and FANCI (PubMed16916645, PubMed17938197, PubMed19111657, PubMed19589784). May contribute to ubiquitination and degradation of BRCA1 (PubMed19887602). In vitro able to promote polyubiquitination using all seven ubiquitin Lys residues but may prefer ‘Lys-11’-, ‘Lys-27’-, ‘Lys-48’- and ‘Lys-63’-linked polyubiquitination (PubMed20061386). {ECO0000269|PubMed16916645, ECO0000269|PubMed17938197, ECO0000269|PubMed19111657, ECO0000269|PubMed19589784, ECO0000269|PubMed19887602, ECO0000269|PubMed20061386, ECO0000269|PubMed28437106}.

Ckap2: Human Uniprot function (Human CKAP2): Possesses microtubule stabilizing properties. Involved in regulating aneuploidy, cell cycling, and cell death in a p53/TP53-dependent manner (by similarity). {ECO0000250}.

Lilra3: Human Uniprot function (Human LILRA6): May act as receptor for class I MHC antigens. LIRA6_HUMAN,Q6PI73

Lilrb3l: Human Uniprot function (Human LILRA5): May play a role in triggering innate immune responses. Does not seem to play a role for any class I MHC antigen recognition. {ECO:0000269|PubMed:16675463}.

No liver genes in male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive upregulated genes with a calculated BMD were Gsta2 (glutathione S-transferase alpha 2), Gsta5 (glutathione S-transferase alpha 5), Crot (carnitine O-octanoyltransferase), Slc27a2 (solute carrier family 27 member 2), Acaa1a (acetyl-CoA acyltransferase 1A), and Acaa1b (acetyl-Coenzyme A acyltransferase 1B) with BMDs (BMD_L_s) of 5.725 (1.686), 5.725 (1.686), 7.423 (5.757), 7.622 (5.499), 8.417 (7.129), and 8.417 (7.129) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Egr1 (early growth response 1), Zfp354a (zinc finger protein 354A), Tsku (tsukushi, small leucine rich proteoglycan), and Cyp7a1 (cytochrome P450 family 7 subfamily A member 1) with BMDs (BMD_L_s) of 0.750 (0.186), 0.835 (0.271), 1.384 (0.541), and 5.721 (0.985) mg/kg, respectively.

In female rats, the most sensitive upregulated liver genes with a calculated BMD were Dao (D-amino-acid oxidase), Ephx2 (epoxide hydrolase 2), Ehhadh (enoyl-CoA hydratase and 3-hydroxyacyl CoA dehydrogenase), Cyp2b1 (cytochrome P450, family 2, subfamily b, polypeptide 1), Loc108348266/Cyp2b1 (cytochrome P450 2B1), Cyp2c6v1 (cytochrome P450, family 2, subfamily C, polypeptide 6, variant 1), Loc100911718 (cytochrome P450 2C6-like), and Ech1 (enoyl-CoA hydratase 1) with BMDs (BMD_L_s) of 6.134 (2.436), 6.441 (2.664), 7.300 (5.266), 7.456 (5.106), 7.456 (5.106), 9.829 (7.252), 9.829 (7.252), and 9.874 (6.591) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were A2m (alpha-2-macroglobulin) and Loc100911545/A2m (alpha-2-macroglobulin), both with a BMD (BMD_L_) of 1.163 (0.179) mg/kg.

None of the top 10 most sensitive kidney genes in male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive upregulated genes with a calculated BMD were Insig1 (insulin induced gene 1), Srebf1 (sterol regulatory element-binding transcription factor 1), Fads1 (fatty acid desaturase 1), Ppard (peroxisome proliferator-activated receptor delta), Decr1 (2,4-dienoyl-CoA reductase 1), Acot2 (acyl-CoA thioesterase 2), Acaa1a (acetyl-CoA acyltransferase 1A), Acaa1b (acetyl-Coenzyme A acyltransferase 1B), and Fasn (fatty acid synthase) with BMDs (BMD_L_s) of 7.612 (5.589), 8.745 (5.224), 9.357 (6.123), 9.934 (5.754), 12.862 (10.721), 13.201 (10.994), 13.398 (11.228), 13.398 (11.228), and 13.486 (11.223) mg/kg, respectively. One gene, Loc100911814/Spink1l (glycine decarboxylase), was downregulated with a BMD (BMD_L_) of 0.510 (0.212) mg/kg.

In female rats, the most sensitive upregulated kidney genes with a calculated BMD were Cdca3 (cell division cycle associated 3), Pck1 (phosphoenolpyruvate carboxykinase 1), Ube2t (ubiquitin-conjugating enzyme E2T), Srebf1 (sterol regulatory element-binding transcription factor 1), Ckap2 (cytoskeleton associated protein 2), Lilra3 (leukocyte immunoglobulin-like receptor, subfamily A (without TM domain), member 3), Lilrb3l (leukocyte immunoglobulin-like receptor, subfamily B (with TM and ITIM domains), member 3-like), and Acaa1a (acetyl-CoA acyltransferase 1A) with BMDs (BMD_L_s) of 2.619 (0.978), 5.515 (1.341), 10.991 (7.866), 11.236 (4.944), 12.122 (8.470), 17.020 (10.650), 17.020 (10.650), and 17.682 (14.617) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Slc10a1 (solute carrier family 10 member 1) and Cyp2c24 (cytochrome P450, family 2, subfamily c, polypeptide 24) with BMDs (BMD_L_s) of 7.968 (6.075) and 10.565 (7.636) mg/kg, respectively.