# Background

Perfluorohexanesulfonamide (PFHxSAm) (CASRN: 41997-13-1, U.S. Environmental Protection Agency [EPA] Chemical Dashboard: DTXSID50469320,^1^ PubChem CID: 11603678,^2^ European Committee Number: 816-398-1^3^) is a member of the per- and polyfluoroalkyl class of compounds that are associated with numerous toxicological effects.^4^ There is widespread human exposure to this class of compounds.^5,6^ The predicted upper 95th percentile human exposure to PFHxSAm is 0.0000563 mg/kg body weight/day.^7^ A review of the existing literature failed to identify any in vivo toxicological information on PFHxSAm, and according to the EPA Chemical Dashboard, no quantitative risk assessment values or quantitative hazard values exist for this test article.^8^ Publicly available information on PFHxSAm can be found in PubChem^2^ and the EPA Chemical Dashboard.^1^

Recent studies have demonstrated that short-term in vivo gavage studies coupled with transcriptomics on select target organs can be used to estimate a biological potency that provides a reasonable approximation of toxicological potency in long-term guideline toxicological assessments.^9^ To estimate biological potency and gain insight into the nature of biological changes elicited by PFHxSAm, the National Institute of Environmental Health Sciences performed a short-term in vivo biological potency study of male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. The results of this study are presented in this report.