# Appendix F Supplemental Data

The following supplemental files are available at https://doi.org/10.22427/NIEHS-DATA-NIEHS-10.^29^

## F.1 Apical Benchmark Dose Analysis

Mean Body Weight Summary

Organ Weights Summary

Clinical Chemistry Summary

Hematology Summary

Hormone and Enzymes Summary

BMD, NOEL and LOEL Summary for Apical Endpoints

Male BMD Apical Endpoints Model Fits

Female BMD Apical Endpoints Model Fits

BMD Model Recommendation Selection Rules

Read Me

Male Model Parameters

Female Model Parameters

BMDs code package

## F.2 Genomic Benchmark Dose Analysis

BMDExpress Project File (bm2 format)

Top 10 Genes Ranked by Potency of Perturbation_Kidney

Top 10 GO Biological Process Gene Sets_Kidney

Top 10 Genes Ranked by Potency of Perturbation_Liver

Top 10 GO Biological Process Gene Sets_Liver

BMDExpress Expression Data_Kidney_Female

BMDExpress Expression Data_Kidney_Male

BMDExpress Expression Data_Liver_Female

BMDExpress Expression Data_Liver_Male

BMDExpress Individual Gene BMD Results_Kidney_Male

BMDExpress GO Biological Process Deduplicated BMD Results_Kidney_Male

BMDExpress Individual Gene BMD Results_Kidney_Female

BMDExpress GO Biological Process Deduplicated BMD Results_Kidney_Female

BMDExpress Individual Gene BMD Results_Liver_Male

BMDExpress GO Biological Process Deduplicated BMD Results_Liver_Male

BMDExpress Individual Gene BMD Results_Liver_Female

BMDExpress GO Biological Process Deduplicated BMD Results_Liver_Female

BMDExpress Prefilter Results_ Kidney _Female

BMDExpress Prefilter Results_ Kidney _Male

BMDExpress Prefilter Results_ Liver _Female

BMDExpress Prefilter Results_ Liver _Male

Animal and Fastaq Metadata

Kidney Principal Components Analysis Files

Liver Principal Components Analysis Files

Individual Gene BMD Analysis Results File

BMDExpress Software

BMDExpress Project File (JSON format)

GO Biological Process BMD Analysis Results

## F.3 Study Tables

I04 – Mean_Body_Weight_Summary

I05 – Clinical_Observations_Summary

PA06 – Organ_Weights_Summary

PA41 – Clinical_Chemistry_Summary

PA43 – Hematology Summary

PA48 – Summary of Tissue Concentration

R07 – Hormone_Summary

## F.4 Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Hormone Data

Individual Animal Organ Weight Data

Individual Animal Hematology Data

Individual Animal Tissue Concentration Data