# Appendix B Animal Identifiers

Table B-1 Animal Numbers and FASTQ Data File Names

Animal Number | Sex | Group | Dose (mg/kg) | Survived to Study Termination | Tissue | FASTQ File ID
101 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-101
101 | Male | Vehicle control | 0 | Yes | Liver | Plate1-101
102 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-102
102 | Male | Vehicle control | 0 | Yes | Liver | Plate1-102
103 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-103
103 | Male | Vehicle control | 0 | Yes | Liver | Plate1-103
104 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-104
104 | Male | Vehicle control | 0 | Yes | Liver | Plate1-104
105 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-105
105 | Male | Vehicle control | 0 | Yes | Liver | Plate1-105
106 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-106
106 | Male | Vehicle control | 0 | Yes | Liver | Plate1-106
107 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-107
107 | Male | Vehicle control | 0 | Yes | Liver | Plate1-107
108 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-108
108 | Male | Vehicle control | 0 | Yes | Liver | Plate1-108
109 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-109
109 | Male | Vehicle control | 0 | Yes | Liver | Plate1-109
110 | Male | Vehicle control | 0 | Yes | Kidney | Plate5-110
110 | Male | Vehicle control | 0 | Yes | Liver | Plate1-110
111 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-111
111 | Female | Vehicle control | 0 | Yes | Liver | Plate1-111
112 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-112
112 | Female | Vehicle control | 0 | Yes | Liver | Plate1-112
113 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-113
113 | Female | Vehicle control | 0 | Yes | Liver | Plate1-113
114 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-114
114 | Female | Vehicle control | 0 | Yes | Liver | Plate1-114
115 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-115
115 | Female | Vehicle control | 0 | Yes | Liver | Plate1-115
116 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-116
116 | Female | Vehicle control | 0 | Yes | Liver | Plate1-116
117 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-117
117 | Female | Vehicle control | 0 | Yes | Liver | Plate1-117
118 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-118
118 | Female | Vehicle control | 0 | Yes | Liver | Plate1-118
119 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-119
119 | Female | Vehicle control | 0 | Yes | Liver | Plate1-119
120 | Female | Vehicle control | 0 | Yes | Kidney | Plate5-120
120 | Female | Vehicle control | 0 | Yes | Liver | Plate1-120
121 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-121
121 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-121
122 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-122
122 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-122
123 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-123
123 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-123
124 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-124
124 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-124
125 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-125
125 | Male | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-125
126 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-126
126 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-126
127 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-127
127 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-127
128 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-128
128 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-128
129 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-129
129 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-129^a^
130 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Kidney | Plate5-130
130 | Female | Perfluorohexanesulfonamide | 0.15 | Yes | Liver | Plate1-130
131 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-131
131 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-131
132 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-132
132 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-132
133 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-133
133 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-133
134 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-134
134 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-134
135 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-135
135 | Male | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-135
136 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-136
136 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-136
137 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-137
137 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-137
138 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-138
138 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-138
139 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-139
139 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-139
140 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Kidney | Plate5-140
140 | Female | Perfluorohexanesulfonamide | 0.5 | Yes | Liver | Plate1-140
141 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-141
141 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-141
142 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-142
142 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-142
143 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-143
143 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-143
144 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-144
144 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-144
145 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-145
145 | Male | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-145
146 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-146
146 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-146
147 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-147
147 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-147
148 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-148
148 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-148
149 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-149
149 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-149
150 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Kidney | Plate5-150
150 | Female | Perfluorohexanesulfonamide | 1.4 | Yes | Liver | Plate1-150
151 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-151
151 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-151
152 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-152
152 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-152
153 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-153
153 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-153
154 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-154
154 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-154
155 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-155
155 | Male | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-155
156 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-156
156 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-156
157 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-157
157 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-157
158 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-158
158 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-158
159 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-159
159 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-159
160 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Kidney | Plate5-160
160 | Female | Perfluorohexanesulfonamide | 4.0 | Yes | Liver | Plate1-160
161 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-161
161 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-161
162 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-162
162 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-162
163 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-163
163 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-163
164 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-164
164 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-164
165 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-165
165 | Male | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-165
166 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-166
166 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-166
167 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-167
167 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-167
168 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-168
168 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-168
169 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-169
169 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-169
170 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Kidney | Plate5-170
170 | Female | Perfluorohexanesulfonamide | 12.0 | Yes | Liver | Plate1-170
171 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-171
171 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-171
172 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-172
172 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-172
173 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-173
173 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-173
174 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-174
174 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-174
175 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-175
175 | Male | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-175
176 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-176
176 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-176
177 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-177
177 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-177
178 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-178
178 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-178
179 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-179
179 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-179
180 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Kidney | Plate5-180
180 | Female | Perfluorohexanesulfonamide | 37.0 | Yes | Liver | Plate1-180
181 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-181
181 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-181
182 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-182
182 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-182
183 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-183
183 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-183
184 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-184
184 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-184
185 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-185
185 | Male | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-185
186 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-186
186 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-186
187 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-187
187 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-187
188 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-188
188 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-188
189 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-189
189 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-189
190 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Kidney | Plate5-190
190 | Female | Perfluorohexanesulfonamide | 111.0 | Yes | Liver | Plate1-190
191 | Male | Perfluorohexanesulfonamide | 333.0 | No | None | NA
192 | Male | Perfluorohexanesulfonamide | 333.0 | No | None | NA
193 | Male | Perfluorohexanesulfonamide | 333.0 | No | None | NA
194 | Male | Perfluorohexanesulfonamide | 333.0 | No | None | NA
195 | Male | Perfluorohexanesulfonamide | 333.0 | No | None | NA
196 | Female | Perfluorohexanesulfonamide | 333.0 | No | None | NA
197 | Female | Perfluorohexanesulfonamide | 333.0 | No | None | NA
198 | Female | Perfluorohexanesulfonamide | 333.0 | No | None | NA
199 | Female | Perfluorohexanesulfonamide | 333.0 | No | None | NA
200 | Female | Perfluorohexanesulfonamide | 333.0 | No | None | NA
201 | Male | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
202 | Male | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
203 | Male | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
204 | Male | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
205 | Male | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
206 | Female | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
207 | Female | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
208 | Female | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
209 | Female | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA
210 | Female | Perfluorohexanesulfonamide | 1,000.0 | No | None | NA

NA = no transcriptomics data collected for selected animal.

^a^ Removed due to principal component analysis/hierarchical cluster analysis outlier.