# Preface

Exposures to an increasing number of substances in our environment are being recognized as affecting human neurological development. The purpose of this report is to provide information to assist in determining if a given psychometric test is adequate for assessing a specific neurobehavioral domain or trait in human studies of neurotoxicants. Psychometric tests used in epidemiology studies that were reviewed as part of the U.S. Environmental Protection Agency’s Integrated Risk Information System assessment of methylmercury were selected for review. The reviewed tests included those that were widely used in this literature, as well as those used frequently in studies of other neurotoxicants.

The psychometric tests were assigned to broad neurodevelopmental domains, and principles were developed and used to evaluate 81 psychometric tests for reliability, validity, normative data, and standardized methods for administering the tests. This report provides examples of factors that could present problems and introduce bias in the test results. The examples explain elements that would lead to different levels of bias and cover many aspects of study performance. We hope this information is useful to regulatory agencies charged with interpreting and evaluating the quality of epidemiology studies using these psychometric tests, and to the research community in designing epidemiology studies to assess factors affecting neurobehavior.