# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

ISSN: 2768-5632

DOI: https://doi.org/10.22427/NIEHS-01

Report Series: NIEHS Report Series

Report Series Number: 01

Official citation: White RF, Braun JM, Kopylev L, Segal D, Sibrizzi CA, Lindahl AJ, Hartman PA, Bucher JR. 2022. NIEHS report on evaluating features and application of neurodevelopmental tests in epidemiological studies. Research Triangle Park, NC: National Institute of Environmental Health Sciences. NIEHS Report 01.