# Peer Review

The Division of the National Toxicology Program (DNTP) at the National Institute of Environmental Health Sciences (NIEHS) conducted an external peer review of the draft NIEHS Report on Evaluating Features and Application of Neurodevelopmental Tests in Epidemiological Studies by letter in May 2021 by the experts listed below. Reviewer selection and document review followed established DNTP practices. The reviewers were charged to:

1. Peer review the draft NIEHS Report on Evaluating Features and Application of Neurodevelopmental Tests in Epidemiological Studies.
2. Comment on whether the draft document and draft database are clearly stated and objectively presented.

DNTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Kim N. Dietrich, Ph.D.
  Professor Emeritus, Department of Environmental Health, Division of Epidemiology and Biostatistics
  University of Cincinnati College of Medicine
  Cincinnati, Ohio, USA
- Nancy Fiedler, Ph.D.
  Deputy Director and Professor, Environmental and Occupational Health Sciences Institute, Exposure Science and Epidemiology
  Rutgers University
  New Brunswick, New Jersey, USA