# References

Anderko L, Braun J, Auinger P. 2010. Contribution of tobacco smoke exposure to learning disabilities. J Obstet Gynecol Neonatal Nurs. 39(1):111–117. 10.1111/j.1552-6909.2009.01093.x 20409109
Anderson PJ, Burnett A. 2017. Assessing developmental delay in early childhood — Concerns with the Bayley-III scales. Clin Neuropsychol. 31(2):371–381. 10.1080/13854046.2016.1216518 27687612
Bakian AV, Bilder DA, Carbone PS, Hunt TD, Petersen B, Rice CE. 2015. Brief report: Independent validation of autism spectrum disorder case status in the Utah Autism and Developmental Disabilities Monitoring (ADDM) Network Site. J Autism Dev Disord. 45(3):873–880. 10.1007/s10803-014-2187-6 25022251
Bello S, Krogsboll LT, Gruber J, Zhao ZJ, Fischer D, Hrobjartsson A. 2014. Lack of blinding of outcome assessors in animal model experiments implies risk of observer bias. J Clin Epidemiol. 67(9):973–983. 10.1016/j.jclinepi.2014.04.008 24972762
Bhang SY, Yoon J, Sung J, Yoo C, Sim C, Lee C, Lee J, Lee J. 2018. Comparing attention and cognitive function in school children across noise conditions: A Quasi-experimental study. Psychiatry Investig. 15(6):620–627. 10.30773/pi.2018.01.15 29940716
Braun JM. 2017. Early-life exposure to EDCs: Role in childhood obesity and neurodevelopment. Nat Rev Endocrinol. 13(3):161–173. 10.1038/nrendo.2016.186 27857130
Braun JM, Yolton K, Stacy SL, Erar B, Papandonatos GD, Bellinger DC, Lanphear BP, Chen A. 2017. Prenatal environmental chemical exposures and longitudinal patterns of child neurobehavior. Neurotoxicology. 62:192–199. 10.1016/j.neuro.2017.07.027 28736150
Brody JG, Dunagan SC, Morello-Frosch R, Brown P, Patton S, Rudel RA. 2014. Reporting individual results for biomonitoring and environmental exposures: Lessons learned from environmental communication case studies. Environ Health. 13(1):40. 10.1186/1476-069X-13-40 24886515
Calamia M, Markon K, Tranel D. 2012. Scoring higher the second time around: Meta-analyses of practice effects in neuropsychological assessment. Clin Neuropsychol. 26(4):543–570. 10.1080/13854046.2012.680913 22540222
Centers for Disease Control and Prevention (CDC). 2012. Prevalence of autism spectrum disorders—Autism and Developmental Disabilities Monitoring Network, 14 sites, United States, 2008. MMWR Surveill Summ. 61(3):1–19. 22456193
Cuijpers P, Karyotaki E, Andersson G, Li J, Mergl R, Hegerl U. 2015. The effects of blinding on the outcomes of psychotherapy and pharmacotherapy for adult depression: A meta-analysis. Eur Psychiatry. 30(6):685–693. 10.1016/j.eurpsy.2015.06.005 26169475
Engel SM, Villanger GD, Nethery RC, Thomsen C, Sakhi AK, Drover SSM, Hoppin JA, Zeiner P, Knudsen GP, Reichborn-Kjennerud T, et al. 2018. Prenatal phthalates, maternal thyroid function, and risk of attention-deficit hyperactivity disorder in the Norwegian mother and child cohort. Environ Health Perspect. 126(5):057004. 10.1289/EHP2358 29790729
Gallo V, Egger M, McCormack V, Farmer PB, Ioannidis JP, Kirsch-Volders M, Matullo G, Phillips DH, Schoket B, Stromberg U, et al. 2011. STrengthening the Reporting of OBservational studies in Epidemiology—Molecular Epidemiology STROBE-ME: An extension of the STROBE statement. J Clin Epidemiol. 64(12):1350–1363. 10.1016/j.jclinepi.2011.07.010 22030070
Hertz-Picciotto I, Croen Lisa A, Hansen R, Jones Carrie R, van de Water J, Pessah Isaac N. 2006. The CHARGE study: An epidemiologic investigation of genetic and environmental factors contributing to autism. Environ Health Perspect. 114(7):1119–1125. 10.1289/ehp.8483 16835068
Hrobjartsson A, Emanuelsson F, Skou Thomsen AS, Hilden J, Brorson S. 2014. Bias due to lack of patient blinding in clinical trials. A systematic review of trials randomizing patients to blind and nonblind sub-studies. Int J Epidemiol. 43(4):1272–1283. 10.1093/ije/dyu115 24881045
Klatte M, Bergstrom K, Lachmann T. 2013. Does noise affect learning? A short review on noise effects on cognitive performance in children. Front Psychol. 4:578. 10.3389/fpsyg.2013.00578 24009598
Lauritsen MB, Jorgensen M, Madsen KM, Lemcke S, Toft S, Grove J, Schendel DE, Thorsen P. 2010. Validity of childhood autism in the Danish Psychiatric Central Register: Findings from a cohort sample born 1990-1999. J Autism Dev Disord. 40(2):139–148. 10.1007/s10803-009-0818-0 19728067
Lezak MD. 1976. Neuropsychological assessment. New York, NY: Oxford University Press.
Lezak MD. 1995. Neuropsychological assessment. 3rd ed. New York, NY: Oxford University Press.
Lezak MD, Howieson DB, Bigler ED, Tranel D. 2012. Neuropsychological assessment. 5th ed. New York, NY: Oxford University Press.
Lezak MD, Howieson DB, Loring DW, Hannay HJ, Fischer JS. 2004. Neuropsychological assessment. 4th ed. New York, NY: Oxford University Press.
Linnet KM, Wisborg K, Secher NJ, Thomsen PH, Obel C, Dalsgaard S, Henriksen TB. 2009. Coffee consumption during pregnancy and the risk of hyperkinetic disorder and ADHD: A prospective cohort study. Acta Paediatr. 98(1):173–179. 10.1111/j.1651-2227.2008.00980.x 18764862
McNeish D, Wolf MG. 2020. Thinking twice about sum scores. Behav Res Methods. 52(6):2287–2305. 10.3758/s13428-020-01398-0 32323277
Morris SE, Cuthbert BN. 2012. Research Domain Criteria: Cognitive systems, neural circuits, and dimensions of behavior. Dialogues Clin Neurosci. 14(1):29–37. 10.31887/DCNS.2012.14.1/smorris 22577302
National Toxicology Program (NTP). 2022. NIEHS 1: Chemical Effects in Biological Systems (CEBs) data repository. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program. 10.22427/NIEHS-DATA-NIEHS-01
Needleman HL. 1990. What can the study of lead teach us about other toxicants? Environ Health Perspect. 86:183–189. 10.1289/ehp.9086183 2205488
Nicholas JS, Carpenter LA, King LB, Jenner W, Wahlquist A, Logan S, Charles JM. 2012. Completeness of case ascertainment for surveillance of autism spectrum disorders using the Autism developmental disabilities monitoring network methodology. Disabil Health J. 5(3):185–189. 10.1016/j.dhjo.2012.03.004 22726859
Nisbett RE, Aronson J, Blair C, Dickens W, Flynn J, Halpern DF, Turkheimer E. 2012. Intelligence: New findings and theoretical developments. Am Psychol. 67(2):130–159. 10.1037/a0026699 22233090
Rimvall MK, Elberling H, Rask CU, Helenius D, Skovgaard AM, Jeppesen P. 2014. Predicting ADHD in school age when using the Strengths and Difficulties Questionnaire in preschool age: A longitudinal general population study, CCC2000. Eur Child Adolesc Psychiatry. 23(11):1051–1060. 10.1007/s00787-014-0546-7 24737124
Roberts AL, Lyall K, Hart JE, Laden F, Just AC, Bobb JF, Koenen KC, Ascherio A, Weisskopf MG. 2013. Perinatal air pollutant exposures and autism spectrum disorder in the children of nurses’ health study II participants. Environ Health Perspect. 121(8):978–984. 10.1289/ehp.1206187 23816781
Rose G. 1985. Sick individuals and sick populations. Int J Epidemiol. 14(1):32–38. 10.1093/ije/14.1.32 3872850
Rose G. 2001. Sick individuals and sick populations. Int J Epidemiol. 30(3):427–432, discussion 433–424. 10.1093/ije/30.3.427 11416056
Saltaji H, Armijo-Olivo S, Cummings GG, Amin M, da Costa BR, Flores-Mir C. 2018. Influence of blinding on treatment effect size estimate in randomized controlled trials of oral health interventions. BMC Med Res Methodol. 18(1):42. 10.1186/s12874-018-0491-0 29776394
Sattler JM. 2001. Assessment of children: Cognitive applications. 4th ed. San Diego, CA: Jerome M. Sattler, Inc.
Scharfen J, Jansen K, Holling H. 2018. Retest effects in working memory capacity tests: A meta-analysis. Psychon Bull Rev. 25(6):2175–2199. 10.3758/s13423-018-1461-6 29907925
Shelton JF, Geraghty EM, Tancredi DJ, Delwiche LD, Schmidt RJ, Ritz B, Hansen RL, Hertz-Picciotto I. 2014. Neurodevelopmental disorders and prenatal residential proximity to agricultural pesticides: The CHARGE Study. Environ Health Perspect. 122(10):1103–1109. 10.1289/ehp.1307044 24954055
Shield BM, Dockrell JE. 2008. The effects of environmental and classroom noise on the academic attainments of primary school children. J Acoust Soc Am. 123(1):133–144. 10.1121/1.2812596 18177145
Spreen O, Strauss E. 1991. A compendium of neuropsychological tests: Administration, norms, and commentary. 1st ed. New York, NY: Oxford University Press.
Spreen O, Strauss E. 1998. A compendium of neuropsychological tests: Administration, norms, and commentary. 2nd ed. New York, NY: Oxford University Press.
Strauss E, Sherman EMS, Spreen O. 2006. A compendium of neuropsychological tests: Administration, norms, and commentary. 3rd ed. New York, NY: Oxford University Press.
Suren P, Bakken IJ, Aase H, Chin R, Gunnes N, Lie KK, Magnus P, Reichborn-Kjennerud T, Schjolberg S, Oyen AS, et al. 2012. Autism spectrum disorder, ADHD, epilepsy, and cerebral palsy in Norwegian children. Pediatrics. 130(1):e152–e158. 10.1542/peds.2011-3217 22711729
Wechsler D. 2002. Wechsler preschool and primary scale of intelligence. San Antonio, TX: The Psychological Corporation.
Wechsler D. 2003. Wechsler Intelligence Scale for Children - 4th ed: Administration and scoring manual. San Antonio, TX: PsychCorp by Harcourt Assessment, Inc.
Weiss B. 2000. Vulnerability of children and the developing brain to neurotoxic hazards. Environ Health Perspect. 108 Suppl 3(Suppl 3):375–381. 10.1289/ehp.00108s3375 10852831
White RF. 1992. Clinical syndromes in adult neuropsychology: The practitioner’s handbook. Amsterdam: Elsevier.
White RF. 2004. Neuropsychological assessments in children from a longitudinal perspective for the National Children’s Study. White Paper for NIH, Fall, 2004. http://nationalchildrensstudy.gov/research/analytic_reports/upload/Neuropsychological-Assessments-in-Children-from-a-Longitudinal-Perspective-for-the-National-Children-s-S.
White RF. 2011. Cognitive disorders in adults. The Oxford Handbook of clinical psychology. Oxford: Oxford University Press; Chapter 24.
White RF, Campbell R, Echeverria D, Knox SS, Janulewicz P. 2009. Assessment of neuropsychological trajectories in longitudinal population-based studies of children. J Epidemiol Community Health. 63 Suppl 1:i15–i26. 10.1136/jech.2007.071530 19098136
White RF, Cohen RF, Gerr F, Green R, Lezak M, Lybarger J, Mack J, Silbergeld E, Valciukas J. 1994. Criteria for progressive modification of neurobehavioral batteries. Neurotoxicol Teratol. 16:511–524. 10.1016/0892-0362(94)90130-9 7845334
White RF, Proctor S. 1992. Research and clinical criteria for the development of neurobehavioral test batteries. J Occup Med. 34:140–148. 10.1097/00043764-199202000-00013 1597768
White RF, Reuben AS. In Press. Environmental toxicities including lead. In: Brown GG, Crosson BA, Haaland KY, King TZ, editors. APA Handbook of Neuropsychology: Vol 1 Neurobehavioral Disorders and Conditions: Accepted Science and Open Questions. Washington, DC: American Psychological Association.
Wiggins LD, Baio J, Schieve L, Lee LC, Nicholas J, Rice CE. 2012. Retention of autism spectrum diagnoses by community professionals: Findings from the Autism and Developmental Disabilities Monitoring Network, 2000 and 2006. J Dev Behav Pediatr. 33(5):387–395. 10.1097/DBP.0b013e3182560b2f 22580734