# Part 2: Potential Sources of Bias Related to Selection and Administration of Neurodevelopmental Assessments in Epidemiological Studies

The results of neurodevelopmental assessments can be biased by factors related to the attributes of psychometric test(s), features of the study participants, and/or aspects of test administration. Outcome misclassification resulting from measurement error of an outcome by a psychometric test or clinical diagnosis can introduce systematic or random bias depending on whether it is related to the exposure of interest. Non-differential (i.e., random error) outcome misclassification occurs when the bias is unrelated to the exposure of interest and is expected to attenuate the association between the exposure and outcome toward the null. Differential (i.e., systematic error) outcome misclassification occurs when the bias in the outcome is related to the exposure of interest and is expected to change the direction and magnitude of the observed association relative to the true association.

To illustrate these two types of biases, imagine a study estimating the effect of MeHg exposure on children’s IQ that uses two geographically separate populations similar in all regards, except that one population consumes high levels of MeHg-contaminated fish and the other does not. The investigators in this study intend to use study location (i.e., MeHg-contaminated fish consumption) as a proxy of MeHg exposure. A single researcher assesses the IQ of children at the two study sites. Furthermore, imagine that consumption of contaminated fish causes reductions in child IQ. Non-differential misclassification could arise if the researcher inadvertently scores some children’s IQ two points higher than they should have at both study locations. In the absence of other biases, this random error creates “noise” in the data and would be expected to attenuate the association between MeHg (i.e., study location) and IQ toward the null. Differential misclassification could arise if the researcher scored children’s IQ two points lower at the study location that consumed MeHg contaminated fish but did not do so at the other study location. In the absence of other biases, this systematic error would be expected to cause an overestimation of the association between MeHg and IQ.

An overview is presented below that describes how various factors could influence psychometric test performance or scores. Details are provided about the features that a study would have to include to minimize the influence of these factors. Central to evaluating the potential bias from outcome misclassification, criteria are presented for deciding whether a study adequately addresses a given factor that could create bias (Table 1). The specific evaluation levels that were used are very low, low, moderate, and high likelihood of bias (Table 2). Uncertain can be used in cases in which the study authors do not provide sufficient information about a factor. Additional details about each factor are provided in Table 1.

Table 1 Summary of Factors Influencing Neurodevelopmental Test Performance and the Likelihood of Bias

Factor | Likelihood of Bias
Factor | Very Low | Low | Moderate | High | Uncertain
Test Selection | The psychometric test was selected based on existing scientific knowledge about the effects of a given toxicant on nervous system development. This could include knowledge obtained from experimental animal, acute toxicity, case-series, or epidemiological (e.g., occupational or population-based) studies. | The psychometric test was selected because it has been demonstrated to be sensitive to other neurotoxicants or because the study authors are attempting to replicate a prior finding of a study with low likelihood of bias in this domain. The test was selected for convenience or because it was previously used to examine other hypotheses. | N/A | The test is no longer considered a valid measure of the traits it was designed to assess when it was originally developed. | The study authors do not state why the psychometric test was selected.
Age of Participant | The psychometric test is appropriate for the age range of participants being examined in the study. | The psychometric test is age-appropriate for the participants being studied, but the outcome(s) being examined might be more reliably assessed at other ages. | The age-appropriateness of the test or age of the participants is not stated or cannot be determined. | The psychometric test is not appropriate for the age range of participants being examined in the study. | N/A
Test Culture | The psychometric test was developed for the culture of the participants being examined in the study. In cases when the test is being adapted to other cultures, there is evidence from validation or pilot studies in the target population demonstrating the validity and reliability of the adapted test. | In the case of multisite studies, a culturally appropriate test was administered to the participants being examined in the study, exposure was not related to study site, and the investigators took efforts to minimize potential differences in psychometric test performance related to study site. | The psychometric test is not culturally appropriate for the study participants being examined or there is no evidence presented that it is valid or reliable in the population being studied. The cultural appropriateness of the test is not stated. | In the case of multisite studies, there are cultural differences across study sites that could affect psychometric test scores among participants being examined in the study, and study site is related to exposure. | N/A
Test Language | The psychometric test was developed for the primary language of the participants being examined in the study. In cases when a test was translated to another language, translation and back-translation is evident. There is evidence from validation or pilot studies in the target population demonstrating the validity and reliability of the translated test. | The test was translated and back-translated; there is no evidence demonstrating validity or reliability of the translated test in the target population. The test was translated, but not back-translated; there is evidence of validity and reliability of the translated version. | The psychometric test was adapted for another language, but only translated and not back-translated for comparison to the original test, and there is no evidence of validity or reliability of the test in the new language. The study authors do not state if/how the test was translated and whether validity studies were performed. | The psychometric test was not administered in the same language spoken by the study participants. | N/A
Test Score Derivation | Normalized test scores are appropriate for the source population of the study participants (i.e., developed for this source population). Alternatively, raw scores are used in analyses wherein norms do not exist and raw scores are adjusted for factors known to influence test performance (e.g., age and sex). | Normalized scores from a comparable target population are applied to the study participants (e.g., United States versus Canada). | Normalized scores from a noncomparable target population are applied to the study participants (e.g., United States versus China). Raw scores are used and there are no adjustments for factors predictive of the measured trait. | N/A | The study authors do not state which scores were used or do not provide details about score derivation.
Standard Test Administration | The psychometric test was developed for the population being studied and there is evidence that it was administered in a standardized manner. | In cases when tests were adapted for the study population, the adapted version is administered in a standardized fashion. There is evidence that the adapted version is reliable across study sites and examiners. Moreover, there is evidence that the adapted test measures the same construct (e.g., cognition, motor skills) in the target population as in the population for which the test was developed (i.e., validity). | In cases when a test was adapted for the study population, the adapted version is administered in a standardized fashion, but there is no evidence of the reliability or validity of the adapted test. | There is no evidence that the adapted test has been administered in a standardized fashion within the study. Reliability and validity of the adapted version has not been demonstrated. | N/A
Examiner Training | A Ph.D.-level investigator with training in psychometric tests trains study staff on how to administer tests and assesses examiner validity and reliability at baseline about every 12 months. Examiners have adequate training and experience administering tests and have special training or experience for unique subpopulations (e.g., children). | A Ph.D.-level investigator trains staff initially, but there is no additional training or testing to ensure continued validity and reliability. Examiners have adequate training and experience administering tests but may not have special training or experience for unique subpopulations (e.g., children). | The study authors do not report features of examiner training and experience. | No staff training by a Ph.D.-level investigator is conducted or the examiners are inexperienced with administering psychometric tests. | N/A
Examiner Blinding | The examiners (or reporters) are blind to each study participant’s exposure at the time of examination(s). | In the case of multisite studies for which participants were selected on the basis of exposure, the investigators make efforts to minimize the potential for an examiner’s knowledge of participant exposure to influence examinations. This includes minimizing examiner effects (i.e., high interrater reliability), providing adequate and repeated refresher training to examiners, and controlling for study site in statistical analyses if warranted. | For single site studies, the examiners (or reporters) are not blind to each study participant’s exposure at the time of examination(s). The study authors do not report on the blinding of examiners or reporters. | In the case of multisite studies for which participants were selected on the basis of exposure, the investigators did not make efforts to minimize potential for examiner’s knowledge of participant exposure to influence examinations. | N/A
Number of Examiners | There is one examiner who administers all psychometric tests and has high reliability. If there are multiple examiners, the interrater reliability is high and examiners are assessed for validity and reliability about every 12 months. Longitudinal assessments are done by the same examiner(s) when feasible. | N/A | There are multiple examiners with uncertain interrater reliability or the interrater reliability is low with any number of examiners. The study authors do not state the number of examiners. | N/A | N/A
Test Environment | The described test conditions are optimized to obtain the best estimate of an individual’s psychometric test score. Rooms are quiet, well lit, and free of distractions. Accommodations are made for pediatric participants. | Test conditions vary, but attempts are made to standardize and optimize the conditions (e.g., tests administered in schools or participant homes). | Test conditions are not standardized or optimized. The study authors do not state the test conditions. | In the case of multisite studies for which participants are selected from sites on the basis of exposure, the testing environment is related to study site and the subject’s performance on the test. | N/A
Longitudinal Measures | The same or a comparable psychometric test is administered by the same examiner (when feasible) at least 12 months apart. Because specific tests may be revised during a longitudinal study, the version of the instrument used must be considered. Best practices can include continuing to use the version of the test initially applied, especially if the adjusted raw score outcomes are utilized or the study aim is to determine if the predictor variables cause test performance to change over time. | The same or a comparable psychometric test is administered by different examiners and used over time, or less than 12 months elapsed between examinations. A comparable test can include a newer version of the test applied earlier to the population, especially if normative outcomes are utilized or if the test undergoes very little change during revision. Sometimes, however, a revised version of a test differs too much from a previously applied version and may not be truly comparable. | Noncomparable psychometric tests are administered on different occasions but are treated as interchangeable. Statistical methods are not appropriate for analyzing repeated measures data. | N/A | The study authors do not state whether the measures are comparable over time. They do not report length of time between measures, number of examiners, or statistical methods.
Clinical Diagnosis | Neurodevelopmental disorder diagnoses are made according to established criteria, confirmed in a subset of individuals using other diagnostic methods or validated using other methods, and do not vary across space and time. | N/A | Diagnoses are not confirmed using another method or diagnostic methods varied over space and time and these differences are not taken into account. It is not clear how diagnoses were made, whether they were confirmed using other methods, or if diagnostic criteria varied over space and time. | Diagnoses are not made according to established criteria. | N/A

N/A = not applicable.

Table 2 Likelihood of Bias for Individual Factors Related to Psychometric Test Administration in Epidemiological Neurodevelopmental Toxicity Studies

Likelihood of Bias | How to Interpret
Very Low | Appropriate study conduct related to the factor and minor deficiencies are not expected to influence the results.
Low | The study has some limitations, but limitations are not likely to be severe or have a notable impact on the results.
Moderate | Identified biases or deficiencies are interpreted as likely to have a notable impact on the results or prevent reliable interpretation of study findings.
High | A judgment that the study conduct relating to the factor introduced a serious flaw that is interpreted to be the primary driver of any observed effect or makes the study uninterpretable. Study is not used without exceptional justification.
Uncertain | The study authors did not present information about the factor and an evaluation of it cannot be conducted.

Factors were identified that influence neurodevelopmental test performance iteratively in consultation with collaborators at DNTP and EPA. The process included starting with a list of factors known to influence test performance given past experience (e.g., participant age, culture, and test conditions). Additional factors specific to studies of MeHg were added based on discussions with EPA collaborators (e.g., score derivation) or from prior assessments of the literature (e.g., blinding).

In some cases, fewer than four levels were applied to each criterion. For some factors, only very low and low were selected because it was determined that the factors were unlikely to affect the interpretation of the results. In other cases, only very low and high were selected for likelihood of bias when it was determined that the factor did not have finer gradations. Finally, instances were noted for which the absence of information about a given factor warrants a rating of moderate risk of bias because the failure to address this factor increases the likelihood of biasing a study’s results or reduces the validity of the psychometric test(s) administered to the participants. In other cases, when a given factor is not discussed, there is not necessarily a high likelihood of bias that would systematically distort psychometric test performance. However, the failure to address this factor could increase random error.

Given that there are a variety of ways to administer psychometric tests—examiner-administered, questionnaire, or computerized—some of the factors discussed below do not apply to certain types of tests. Examiner-administered tests are those for which an examiner is directly administering the test to a participant and is also responsible for scoring responses. Questionnaires include participant, teacher, or parent ratings of the participant’s thoughts, behaviors, or feelings. Computerized tests are those that are completed via a laptop, desktop computer, or tablet after standardized instructions are provided by an examiner or the software.

Application of the evaluative criteria for each factor should be applied to each psychometric test that was used for data analysis in a study (or manuscript). Most, if not all, cohort studies examining developmental neurotoxicity have administered a variety of examiner-administered, questionnaire-based, and computerized tests to participants. Thus, it is possible for there to be low risk of bias for one test but a higher risk of bias for another test within the same study.

As noted at the beginning of this document, the evaluation ratings provided in Part I are not meant to provide a definitive determination of whether a psychometric test should be used in a particular setting. Rather, they provide a summary of what is known about each test’s psychometric properties to guide the reader in making such determinations. At the broadest level, an assessment of an outcome’s usefulness and validity will need to consider whether a given factor will affect the internal and external validity of a result. A study’s results could be internally valid even in the presence of biases related to psychometric test administration. For instance, the normative scores used as the outcomes from a psychometric test in a study may not be derived from a reference population that is highly similar to the one used in the study, but the direction and magnitude of the reported association might be similar regardless of how the scores were treated. Approaching the evaluation in this way will help guide decisions about whether a given result is informative for a meta-analysis or risk assessment.

Note that evaluators will need to apply some discretion regarding the context of the specific psychometric test, study location, participants, and other factors when applying the principles described below. For example, with regard to study location, some countries or institutions may only require master’s level training in psychology or neuropsychology to supervise study staff administering psychometric tests, but in other countries, doctoral-level training may be required. As another example, specifically with regard to psychometric test translation, translation and back-translation are important for all tests, with pilot testing of the translated versions conducted before the study begins.

Four factors are less applicable to questionnaires—examiner training, examiner blinding, number of examiners, and test environment. It is possible that these factors could introduce random error into the measurement of a trait. For example, if an examiner “guides” the respondent to indicate abnormal functioning by saying that this is what the study is looking for in a particular exposure situation, the outcome could be biased. This can be avoided by providing scripts to examiners to use when they hand questionnaires to respondents. In addition, participant responses on a questionnaire might vary if they are in a quiet room at the study clinic versus a noisy room in their residence. However, systematic bias related to aspects of test administration seems less likely using self-administered questionnaires.

## Test Attributes

Several attributes need to be considered when evaluating the use or features of a psychometric test. In Part 1 of this report, details are provided about the psychometric properties and features of specific tests. This section describes more broadly how specific test characteristics influence their use and interpretation in population-based studies.

### Selection of Psychometric Tests

Selection of appropriate psychometric tests for research assessing toxicant effects on the developing nervous system requires an understanding of the toxicant and research question. The selection of tests will depend on the toxicant of interest. Different toxicants affect different nervous system pathways, and thus affect specific domains or subdomains of neurobehavioral function. A null result may not indicate a lack of neurotoxicity of the chemical being investigated, but rather that the toxicant does not affect the biological pathways related to the domain, subdomain, or behavioral outcome measured by the test(s) chosen for the study (i.e., lack of sensitivity).

Ideally, to safeguard against this situation, psychometric tests should be selected based on a review of existing scientific knowledge (e.g., experimental studies in animals, acute toxicity studies or case-series, occupational studies) about the nervous system pathways and structures that are affected by the exposure of interest. Knowledge about mechanisms of neurotoxic action on the nervous system and its structures can be used to select outcomes that are most likely to detect neurotoxic effects. It is important to note that, for some toxicants, there may be no or limited prior literature available to select outcomes that would be most sensitive. In this case, researchers might consider the effects of toxicants with similar structure and modes of action in their choice of outcomes. Alternatively, they might assess a broad range of domains using outcomes with previously documented sensitivity to various neurotoxicants, with the intent of identifying which facets of neurodevelopment are potentially affected by the toxicant of interest.

Less ideally, psychometric tests are selected out of convenience because they are familiar to the researchers, used by other researchers, readily available, or easy to use. In addition, some cohort studies that were designed to evaluate questions about neurodevelopment, but not specifically neurotoxicity, are adapted for use in the field of neurotoxicology. These cohorts often have large sample sizes, relevant covariates, and available biospecimens or environmental samples that can be used to assess neurotoxicant exposure during periods of heightened susceptibility (e.g., pregnancy, childhood). In these cases, the neurodevelopmental outcomes may have been selected to address other research questions or as general assessments of neurodevelopment (e.g., IQ tests, personality tests) without a specific a priori reason to use them for studying a given toxicant. In some cases, this situation may underlie null findings. In general, these sources of data can be helpful in the absence of resources to create new cohorts or conduct new studies.

The “age” of a test is an additional consideration for test selection because psychometric tests are often replaced by newer versions of a test or are phased out of use. Evaluators should consider the length of time between test development and test administration. “Aged” tests may no longer be relevant to contemporaneous populations (e.g., content or language) or their validity and the theoretical constructs on which they are based may no longer be consistent with the latest advances in psychometric testing and neurodevelopment. Assuming that a “dated” test remains valid, it may continue to be used in cases when the test users have already conducted repeated assessments using the same instrument. However, the normed outcomes (e.g., scaled scores) may need to be updated or raw scores, rather than normed scores, may need to be used as outcomes with adjustment for age, sex, or other factors that explain variance in the raw scores. Given the difficulty in determining if an individual test is “dated” at the time of its administration, this factor was not considered as an evaluative criterion in this document.

## Appropriateness of Tests for Assessment

The previous section describes how psychometric properties of individual tests might influence the ability to validly and reliably assess a given domain or subdomain of neurodevelopment. How these features interact with attributes of the population being studied is considered below.

### Participant Age

The age of the participants at the time of test administration is important to consider because virtually all psychometric tests are developed for specific age ranges, and the results of some tests may vary as a function of age. For instance, some tests of cognitive abilities have been developed specifically for preschool children (e.g., Wechsler Preschool and Primary Scale of Intelligence [WPPSI]), whereas others have been developed for school-age children (e.g., Wechsler Intelligence Scale for Children [WISC]) (Wechsler 2002; Wechsler 2003). For a given test, scores might be age-standardized to allow comparisons of psychometric traits across children of different ages.

In some cases, the appropriate age for administering a given test is stated in years. Unless stated otherwise, it should be assumed that this is inclusive from the first date of the first year to the last date of the last year (e.g., a test designed for 2- to 5-year-olds is appropriate for children who are greater than or equal to 2 years of age and less than 6 years of age).

Failure to adhere to age ranges recommended by the test developers can lead to invalid results. An egregious example would be to administer tasks that require reading to pre-literate children. Thus, it is essential that the selected psychometric test is designed and validated for the age group of interest and that the test is only administered to age-appropriate subjects.

The values and variability of some psychometric test scores vary as a function of age. For instance, parent-reported child anxiety can increase as children age (Braun et al. 2017). In addition, an environmental toxicant may not be associated with some domains of child cognitive development if the presence or variance of the trait associated with the domain is absent or low, respectively. For example, some executive functions develop later in childhood than others. Moreover, the reliability of a specific domain could be lower at younger ages (e.g., infancy) when performance on a given test may be sensitive to recent feeding or sleeping. For instance, the Mental Development Index of the Bayley Scales of Infant Development-II (BSID-II), a measure of infant and toddler cognitive abilities, has fair reproducibility in the first 3 years of life, whereas the full-scale IQ of the Wechsler instruments, another measure of cognitive abilities, has excellent reproducibility at later ages (Braun et al. 2017). At earlier ages, the variability in test scores arises because of the highly dynamic nature of development and potential for other factors (e.g., lack of sleep, hunger) to have a greater effect on test performance. This variability does not negate the validity of neurodevelopmental assessments at earlier ages but may increase the variance in measures taken at earlier ages (i.e., random error).

Preferably, the age of test administration is selected based on a priori knowledge of the specific domain being assessed in order to reduce within-person variance or age-related changes in the trait associated with the domain. Alternatively, longitudinal measures of the domain can be collected to reduce within-person variance as well as to examine the effect of an environmental toxicant exposure on trajectories of a domain.

A final point to consider with regard to age is the length of the psychometric test battery. Scores obtained during a lengthy test battery might not reflect a participant’s true abilities. For instance, infants and toddlers usually will not tolerate more than 75 minutes of testing, whereas school-aged children can tolerate 2–3 hours. In addition to length of the test battery and age-appropriateness of the test, investigators ideally should provide information about whether participants received adequate breaks between tests or tests were completed during multiple visits.

### Culture

Psychometric test results could be biased to specific cultural groups in ways that affect performance. Even tests like the Raven’s Progressive Matrices, which are thought to be “culturally fair,” favor participants who have formal schooling that teaches them to organize data into rows and columns (Nisbett et al. 2012). Other examples include using test items (e.g., analogies) that might be unfamiliar to certain cultures.

Ideally, psychometric tests are selected so that cultural biases are minimized. Initially, pilot testing of psychometric tests in the study population of interest can provide data to ensure that there are not specific items or composite/subscale scores that are lower than expected, that the participants understand test expectations, and that items are correctly ordered for difficulty. In the absence of these problems, comparison of normed scores in the study participants to other reference populations can aid in identifying cultural bias. Lower-than-average normalized scores in the study participants may be indicative of cultural bias. Finally, in multisite studies, it is important to consider whether there are cultural differences across study sites that might influence test performance. This can result in systematic bias if study site is related to toxicant exposure(s).

### Language

Some psychometric tests have been translated into different languages to facilitate measurement of various domains in populations around the world; however, test translation may introduce bias if individual test items are not appropriately translated. In some cases, test developers provide validated test translations that are readily available (e.g., Pearson products).

Ideally, the psychometric test was developed for the setting-specific language or the test publishers have endorsed specific versions of the test in other languages. Less ideally, the test is translated by the investigators into the setting-specific language. If this is done, the test should first be translated to the new language by one bilingual translator and then back-translated to the original language by another bilingual translator and piloted before applied to the study population.

### Score Derivation

Raw scores from psychometric tests are usually converted to scaled scores, T-scores, or standard scores using data derived from a reference population—often a representative sample of the U.S. population. Scaling of scores is done to account for age- and sometimes sex-specific differences in the means and variances of raw scores, thus allowing comparison of scores across different subgroups. It is important to note that subgroup-specific means and variances may be specific to the reference population and not generalizable to other populations. Thus, derived scores can vary in different populations through two mechanisms:

1. If the mean of raw scores from the study participants is higher/lower than the reference population’s raw scores, then the mean of the scaled, T-, or standard scores will be higher/lower.
2. If the variance of raw scores from the study participants is higher/lower than the reference population’s raw scores, then the variance of the scaled, T-, or standard scores will be higher/lower.

The presence of a shift in the mean and/or variance of raw scores can be assessed if the study authors report the mean and variance of the scaled, T-, or standard scores in their entire group of study participants and ideally across subgroups that are used to derive scaled, T-, or standard scores. However, if the raw score mean or variance is correlated with the exposure, then the exposure-outcome association could be biased in an unpredictable way. This would be difficult to verify unless the study authors report the raw score means and variances by exposure and covariates.

Ideally, the study participants are drawn from the same or a comparable source population as the reference sample. In other cases, population-specific references may be available (e.g., Canadian reference for Wechsler IQ tests). If a comparable reference is not available, the raw scores from the instrument can be used as the outcome. Ideally, a model using the raw score as the outcome would adjust for the same variables that are used to derive scaled, T-, or standard scores (e.g., age and sex). There is the potential for moderate risk of bias if adjustments are not made for these variables when the variable(s) are related to raw score values. Most critical would be if these factors are related to exposure. Less critical is when these variables are not related to the exposure, but still explain variation in the raw scores. In the latter case, adjusting for them can result in more precise estimates of the exposure-outcome relationship.

As noted in the Normative Data section, the nature of some raw scores may preclude using them as the outcome in regression models. For example, the Bayley Scales have infants or children complete a different set and number of items based on their age. Thus, the raw scores may not be equivalent across individuals. While a variety of methods could be used to create new scores (e.g., summed scores, PCA-derived scores), they have various strengths and limitations (McNeish and Wolf 2020), and a full evaluation of these methods is beyond the scope of this document.

## Factors Related to Test Administration

### Standardized Test Administration

Psychometric tests need to be administered in a standardized fashion to ensure that variations in administration procedures do not unduly influence test scores. Standardized administration of psychometric tests enhances the confidence that test results and findings are comparable across individuals, study sites, and populations.

The standardized administration of many psychometric tests is detailed in their respective manuals. The goal of providing detailed test administration instructions is to ensure that psychometric tests are administered in the same manner by any test user (e.g., psychometrist, psychologist). These instructions define standard test procedures for components of the test, the test materials used in administering the test, and scoring of participant responses. These manuals often provide word-for-word instructions and questions (“scripts”) to be used in administering the test. The test materials generally include test stimuli, answer sheets, and test administration booklets that should be used for every administration. Finally, the test manuals provide methods and formulas for scoring each item in the test.

Deviations from standardized test administration across participants, study sites, examiners, or populations can produce results that are not comparable with each other. Some deviations from standard procedure as defined by the test manual are described in this document and are common in epidemiological research when psychometric tools are applied to populations aside from the one(s) on which the test was normed. These include changes in the test stimuli or order of stimulus presentation, usually due to cultural factors, and the language in which the test is administered. In these cases, there should be evidence that the administration of the adapted tests is standardized across participants, study sites, and examiners. Moreover, there should be evidence that any adaptations do not threaten the validity and reliability of the test.

### Test Examiner

An individual’s psychometric test performance can be influenced by factors related to the test examiner. Therefore, a number of specific factors should be in place to ensure that any potential examiner effects on test performance are minimized.

The following factors are potential sources of bias for cases when the examiner is actively administering a test to the participant and is responsible for directly engaging the participant, presenting stimuli, rating the participant’s response, and scoring the responses (e.g., IQ tests). Standardized instructions should be used when instructing participants on how to complete questionnaires (e.g., behavioral rating forms) or computerized tests (e.g., continuous performance tasks).

#### Training

Persons directly administering psychometric tests should have adequate training in and experience with administering psychometric tests to subjects similar to the study participants. Given the intensive nature of administering more complex psychometric tests (e.g., BSID, NEPSY, Brazelton, NNNS), some researchers and clinical professionals believe that they should only be administered by licensed practitioners. Examiners should receive training from a Ph.D.-level investigator with expertise in neuropsychology, clinical psychology, educational psychology, or other closely related discipline. This “expert-level” trainer should have the requisite qualifications and experience to ensure that they can validly and reliably administer the specific tests. Examiners should have specialized training or experience when working with unique subpopulations (e.g., children). More complex or in-depth tests (e.g., NEPSY) require that a highly experienced trainer provides examiners with didactic instruction on the test, hands-on practice to administer the test, and assessment of validity/reliability in subjects similar to the study’s source population.

In addition to having adequate training and experience, examiners should routinely be assessed for drift over time. Test drift can arise if examiners change the way they administer or score specific items over time, resulting in additional variability in test scores. Ideally, a Ph.D.-level investigator who is trained in psychometric test administration assesses each examiner’s validity and reliability about every 12 months. Reliability can be assessed using test-retest correlations with the same examiner administering the test to the same individuals at the same age at the time of testing. A less ideal approach is to have a Ph.D.-level investigator provide refresher training on the specific tests. Finally, multisite studies should ensure that all examiners receive the same initial training to ensure validity and reliability, are routinely checked for validity and reliability, and obtain additional training as needed.

#### Blinding

There is evidence from randomized controlled trials that non-blinded trials report exaggerated effect sizes relative to blinded trials; however, the magnitude of these differences varies according to specific treatments and outcomes (Bello et al. 2014; Cuijpers et al. 2015; Hrobjartsson et al. 2014; Saltaji et al. 2018). It is conceivable that this phenomenon is present in observational studies of neurotoxicants in which examiners or reporters (e.g., caregivers) are not blind to the exposure status of participants. This may arise in studies where staff have access to exposure level data for participants or when exposure biomarker results are reported back to participants or participants’ parents/caregivers (Brody et al. 2014). Indeed, some investigators have reported chemical biomarker results back to participants, especially in community-based participatory research. Ideally, all examiners (or reporters) in observational studies of neurotoxicants should be blind to each participant’s exposure status. This might not be possible in multisite studies for which sites were selected on the basis of exposure. The magnitude of the effect that blinding would have in observational studies of some neurotoxicants is unclear. It is important to note that certain psychometric tests (e.g., computerized tests that involve little interaction with an examiner, self-reported behaviors) may be less susceptible to this source of bias.

#### Number of Examiners

Studies using a larger number of examiners could produce variability in psychometric test scores due to differences in test administration and scoring across examiners compared with studies using a smaller number of examiners. Inter-examiner reliability is typically assessed by having the study’s examiners administer the test to the same individuals at the same age; these data are used to calculate inter-examiner correlations. Ideally, studies should strive for high inter-examiner reliability as measured by Pearson correlations, intraclass correlations coefficients, etc. (Strauss et al. 2006). Moreover, in longitudinal studies, ideally the same examiner(s) should assess participants at subsequent visits if the same psychometric test is administered again. Examiner effects can be assessed by quantifying the reliability of two examiners assessing the same child or by comparing the mean instrument scores across examiners. It is important to note that statistically adjusting for examiners will not correct for differences in interrater validity or reliability. For instance, if an examiner invalidly administered a psychometric test to participants, then statistical adjustment for the examiner will not make these measurements “more” valid as they were never valid.

### Test Administration, Environment, and Conditions

Test performance can be affected by the environment and conditions of test administration. As Strauss notes, optimal conditions are those that facilitate the participants having their best performance possible, whereas standardized conditions ensure that the conditions of the test are as similar as possible across repeated test administrations (Strauss et al. 2006). Therefore, in epidemiological studies, test environments and conditions should be standardized and optimized to ensure that all participants are given the same opportunity for their best performance with as little variation as possible in the method of administration across subjects.

Environmental factors like noise and temperature can influence test performance. Sources of environmental noise (e.g., traffic, conversations) can adversely affect performance on a wide range of psychometric tests (Bhang et al. 2018; Klatte et al. 2013; Shield and Dockrell 2008). Environmental conditions such as excessive heat can also adversely affect psychometric test performance (Klatte et al. 2013; Shield and Dockrell 2008). Conditional factors, like the location of the test (e.g., study clinic versus the participant’s home) or presence of a parent or other caregiver in the room might cause test performance to vary.

Ideally, the test environment is a quiet, well-lit, and private room that is free of distractions. For pediatric participants, age-appropriate furnishings should be provided so that children are able to sit properly and engage with test materials. It can be reasonable to administer psychometric tests in the home or school environment if the environment is modified for the specific test and provisions are made to standardize conditions as much as possible. For assessments of children less than 2 years of age, it is desirable and often necessary for the parent to be present. At older ages, children should be assessed without the caregiver to reduce the potential for that caregiver to influence a child’s performance. Investigators should note instances when test conditions were not optimal and consider excluding these results from statistical analyses.

Participant-level characteristics also need to be considered when administering psychometric evaluations. Time-varying factors like sleep, hunger, and current infections can affect performance on psychometric tests. For instance, children with or recovering from otitis media may have temporary decreases in hearing ability, which in turn can adversely affect test performance. Other factors like loss of mobility, amputation, and visual or hearing impairments can hinder assessment of specific domains or subdomains.

Ideally, participants are healthy enough to have tests administered to them or are able to return for assessments if it is determined that they are too sick to perform optimally. In cases of permanent disabilities that directly affect the ability to complete the test, these participants should not be assessed or should be excluded from statistical analyses. For pediatric assessments, efforts should be made to assess infants/children when they are well rested and have been fed. For older children, breaks should be offered during longer neurodevelopmental assessment batteries.

Finally, it is important to minimize errors that could arise in the scoring and entry of psychometric test data. Recent versions of some tests now have scannable forms, computerized data entry, and automated scoring. While not infallible, these advancements can improve quality control, as they reduce the potential for human errors in data entry and test scoring.

### Longitudinal Studies

Some studies examine the impact of a neurotoxicant on repeated measures of a psychometric test. This can be done to increase statistical power and precision or to determine if the potential effect of a neurotoxicant persists, emerges, or wanes over time (Braun et al. 2017). There are several factors related to the timing of test administration, type of psychometric test, participant follow-up, and statistical analyses that should be considered when evaluating studies with repeated psychometric measures (White 2004).

The amount of time between assessments should be considered because individual test scores can improve due to practice effects on a given instrument. While some instruments like the WPPSI and WISC recommend at least 1 year between administrations (Wechsler 2002; Wechsler 2003), practice effects have also been found to linger for many years (Calamia et al. 2012). In addition, the number of examiners and examiner drift should be considered because different examiners may administer or score tests differently or change their administration/scoring practices over time. This can be curtailed by videotaping or observing sample examiner test administration every few months during a study and/or each time that a new data collection cycle begins.

In some cases, different psychometric instruments can be used to assess a given domain across ages. For instance, the WPPSI is designed to assess cognitive abilities in children 2.5–7.25 years of age, whereas the WISC is designed to assess these same cognitive abilities in children ages 6–16 years. Both Wechsler instruments are intentionally designed to overlap in ages and assess comparable domains, but this is not the case for all psychometric tests. For less comparable instruments, it is important to consider whether different tests assess the same neurodevelopmental domain and are interchangeable.

Ideally, an examiner administers the same or comparable psychometric tests that assess the same neurodevelopmental domain and the same examiner repeatedly assesses a given participant. If testing is carried out frequently, parallel or equivalent tests that assess a domain can be used instead of repeating a subtest. Moreover, examiner drift over time should be periodically assessed. While there are no clear rules about the length of time required to eliminate practice effects, tests should be administered at least 12 months apart (Calamia et al. 2012; Scharfen et al. 2018).

Finally, appropriate statistical techniques must be used to examine repeated measures data (e.g., linear mixed effect models or linear regression with generalized estimating equations). Failure to account for repeated measures within the same individuals will result in inappropriately small standard errors because traditional methods treat repeated observations as independent.

### Clinical Diagnoses

Some studies examine associations between neurotoxicant exposure and risk of diagnosis with a neurodevelopmental disorder (e.g., ADHD, autism spectrum disorders [ASD], or learning disabilities [LD]) (Anderko et al. 2010; Engel et al. 2018; Shelton et al. 2014). Often these studies rely on registries maintained by disease monitoring networks or governments to identify cases with specific neurodevelopmental disorders (Anderson and Burnett 2017; CDC 2012; Engel et al. 2018). In other cases, investigators conduct detailed neurodevelopmental assessments and medical chart reviews to confirm or deny a clinical diagnosis (Hertz-Picciotto et al. 2006).

Case identification and verification are critical issues to consider when evaluating developmental neurotoxicity studies using clinical diagnoses. Ideally, the probability of an individual being diagnosed (or not diagnosed) with a neurodevelopmental disorder should be the same regarding exposure, as well as socioeconomic status, geography, and calendar time. It is important to note that the probability of being diagnosed is not the same as the probability of having the disorder as there could be over- or under-diagnoses in subpopulations.

With regard to case identification, it is critical that standardized definitions of disease be applied to all participants (e.g., Diagnostic and Statistical Manual criteria). Case verification may be accomplished using administrative records (e.g., International Classification of Disease [ICD] codes) or expert review of medical charts, including psychometric tests and other diagnostic information. Individuals reviewing individual participant information should have a master’s or doctoral degree in clinical psychology or related discipline and be blinded to the exposure status of the participants. Methods of case verification should be the same across clinics, providers, or reviewers who make the diagnosis. In addition, the criteria for establishing diagnosis should be stable over time; otherwise, changes must be considered.

Reassuringly, for ASD and ADHD in the United States and Europe, there is evidence that registry-based measures of diagnosis have high levels of agreement with other diagnostic measures of these disorders (Lauritsen et al. 2010; Linnet et al. 2009; Rimvall et al. 2014; Suren et al. 2012). In addition, there is high agreement of parental report of ASD with psychometric instruments used to diagnose the disorder (Roberts et al. 2013). Moreover, for ASD, there is evidence that registries are effective at ascertaining a high proportion of cases (Nicholas et al. 2012). In addition, registry-based diagnoses of ASD have a high degree of agreement with external expert reviewers (e.g., clinical psychologist) and a high degree of temporal stability (Bakian et al. 2015; Wiggins et al. 2012).

Ideally, a study will use the same criteria to establish a diagnosis across clinics or providers and over time while verifying there are no geographical and temporal deviations in how diagnoses are made. Diagnoses should be based on data from at least two sources in a subset of participants (e.g., registry-based diagnosis, caregiver reports of relevant symptoms, external expert review).