# Methodology for Identifying Psychometric Tests and Extracting Test Information

This section describes the methods for identifying and selecting psychometric tests and extracting information on psychometric features of the selected tests. Test selection and information extraction were conducted to support an evaluation of the psychometric features of each test to determine the adequacy of tests in assessing neurodevelopmental or central nervous system (CNS) function in studies of neurotoxicants. Test selection and information extraction were conducted first and are described here. The test evaluation process and test evaluation results (found in Appendix B) are referenced in this section but are described in detail in the Principles for Evaluating Psychometric Tests section of the document.

## Process of Selecting Tests

Specific psychometric tests for evaluation were selected and information on relevant test features was extracted using a set of studies identified from the systematic review and dose-response analysis for the in-progress EPA IRIS toxicological review of MeHg (see protocol for more details https://cfpub.epa.gov/ncea/iris_drafts/recordisplay.cfm?deid=345309; see Introduction for description of the focus on the MeHg literature in this document).

Peer-reviewed and published epidemiological studies compiled by EPA by July 2019 as part of the in-progress EPA IRIS toxicological review of MeHg were reviewed and a list of psychometric tests was developed (n = 134 tests) based on these studies. Next, a multistage process was implemented to identify information to extract for describing the psychometric features of the identified tests. If accessible, physical manuals or electronic copies of test manuals for the identified tests were reviewed as a first step, as these manuals provided the best available primary sources of information. As a secondary source of information, several editions of two academic textbooks on neuropsychological testing, A Compendium of Neuropsychological Tests (Spreen and Strauss 1991; 1998; Strauss et al. 2006) and Neuropsychological Assessment (Lezak 1995; Lezak et al. 2012; Lezak et al. 2004), were manually searched to identify relevant test features in those sources. If access to a test manual was available and/or usable information was identified in these academic textbooks, further information was generally not sought. Tests with information from manuals or academic textbooks were automatically included in the extraction and evaluation process.

In certain cases, when a physical or electronic copy of a manual or information from one of these academic textbooks was not available, peer-reviewed literature (original research and literature reviews) was identified by searching online journal databases for the test name, any related abbreviations, and relevant keywords (e.g., “psychometric,” “valid*,” “reliability”). EBSCO host was used to search multiple online databases, including Medline, CINAHL Complete, PsycARTICLES, PsycINFO, PsycBOOKS, and PsycEXTRA. Titles and abstracts were screened, and full-text articles were obtained if the abstract discussed psychometric properties, factor analyses, or comparisons with other neuropsychological tests. Studies on groups of people with specific conditions that may affect test performance (e.g., deaf patients) were not included. Ultimately, tests were included in the extraction and evaluation process if enough information was available to assess a majority of the evaluation principles (see Principles for Evaluating Psychometric Tests section) following the steps outlined above. After retrieving sources of information for each test, relevant information was extracted and summarized in an Excel spreadsheet (titled “DNT_Test_Information_Extraction_Database.xlsx”; referred to in this document as the “extraction table”; Appendix C).

Some tests were excluded from the extraction and evaluation process due to idiosyncratic features or insufficient information. Tests were identified as idiosyncratic if they appeared in a single MeHg study, were used only in a specific population, and/or were only used in studies later determined to not be conducive to dose-response analysis for the in-progress EPA IRIS toxicological review of MeHg. Tests were categorized as having insufficient information if no manual was available and secondary sources, including peer-reviewed literature, did not provide information to assess a majority of the evaluation principles.

Of the 134 tests initially identified, 81 were included in the extraction and evaluation process (see Appendix A for the lists of included and excluded tests). Thirty-three tests with idiosyncratic features and 20 tests with insufficient information were excluded from the extraction and evaluation process. The number of included tests by information source(s) included:

- Eight tests with information from manuals only
- Twenty tests with information from manuals and academic textbooks
- Two tests with information from manuals and peer-reviewed literature
- Eighteen tests with information from academic textbooks only
- Three tests with information from academic textbooks and peer-reviewed literature
- Thirty tests with information from peer-reviewed literature only

The included tests (n = 81 tests) were organized into broad domains based on a framework previously developed by the co-author Dr. Roberta White (White 2004; 2011; White et al. 2009). These broad domains included omnibus tests (intelligence quotient [IQ], academic achievement, developmental, and neuropsychological assessment batteries); clinical assessment instruments (clinical conditions and mental status assessments); and domain-specific functional tasks (attention, executive function, learning and memory, motor function, social-emotional, verbal/language, and visuospatial tests). Note that some tests may assess multiple domains.

Subtests and subscales within tests that were used in the epidemiological studies from the in-progress EPA IRIS toxicological review of MeHg were also identified; however, information extraction and test evaluation were conducted at the parent-test level and not for specific subtests, given resource constraints that inhibited the assessment of specific features of subtests. While each test evaluated in this document has been categorized by domain, there are cases for which subtests/subscales within omnibus tests assess domain-specific functions. In these cases, for each domain, the identified subtests or subscales are listed in a footnote below their respective domain-specific evaluation table in Appendix B. Please see the Principles for Evaluating Psychometric Tests section for further detail on the evaluation process, the evaluation results (Appendix B), and a description of the how the evaluations may be applicable for these cases.

## Test Information Extraction

The data in the extraction table (Appendix C) for each test include the following:

- Test name and any alternative names
- Test domain
- Test publication date
- Time required for administration
- Appropriate age range for test administration
- Original publication language(s)
- Availability of the test in other languages
- Availability of culturally adapted version(s) of the test
- Source population or culture from which the test was developed
- Test reliability (internal consistency and test-retest)
- Test validation (content, construct, criterion)
- Sensitivity and specificity of the test
- Description of quantitative outcomes provided by the test
- Test standardization or normative data
- Applicability for use as a screening tool for clinical diagnoses
- Training requirements and qualifications for test administrators, and the availability of specific instructions or a test manual
- Appropriate test environment

The sample populations used to develop the test and its norms were described in the extraction table (Appendix C) to the extent possible based on the source material. Direct quotes from the sources of information were extracted when appropriate. If no information was found for an extracted topic, it was recorded that no information was present in the available source materials. The extraction table was used to inform the test evaluation process. During the peer-reviewed literature search process, supplemental information was found for several tests for which information from manuals or academic textbooks had already been extracted. In these cases, this supplemental information was added to the corresponding test extractions.

## Potential Limitations of Test Selection and Data Extraction Approach

One limitation to the selection of tests is that the scope was narrowed to studies identified from in-progress EPA IRIS toxicological review of MeHg. Studies of other well-characterized neurotoxicants (e.g., lead, organophosphate pesticides) might yield additional tests that are relevant to assessing developmental neurotoxicity. While other well-studied neurotoxicants could have been included (e.g., lead), they were beyond the charge’s scope for developing this document. The approach used to select studies and extract data on properties of psychometric tests was limited by a lack of information for 20 of the 134 tests initially identified from in-progress EPA IRIS toxicological review of MeHg. In addition, conducting complete extraction and evaluations at the subtest level for the original 81 included studies was beyond the scope of this effort. Thus, it is possible that subtests may be rated differently from their parent test. Moreover, because the selection of tests was based on the tests used in epidemiological studies identified for in-progress EPA IRIS toxicological review of MeHg, test selection may not reflect the latest versions of tests used for studying other neurodevelopmental toxicants. Despite these limitations, the tests selected and evaluated in this document are considered to be a representative selection of tests for effects in the associated domains that would be applicable for studying an array of neurodevelopmental toxicants, and the principles for evaluating the tests could be applied to future research.

One issue that limited access to test-specific information was that information was often not available for older tests or for those tests that have not been used extensively in research. Thus, in general, lesser-used tests and older tests had less information or a poorer quality of information related to the features included in the extraction table (Appendix C). In addition, the sources of information varied among included tests (e.g., test manuals available for some tests and peer-reviewed literature only for others), which led to variation in the availability and quality of information. As a result, the features of individual psychometric tests were not systematically evaluated using the same types of information sources. The more commonly used tests and those with multiple and contemporaneous editions (e.g., the omnibus IQ tests such as the Wechsler, Stanford-Binet, and Kaufman scales) were originally developed and evaluated using robust processes conducted by the test developers (often commercial entities). Thus, they may have more complete information because of their well-funded, rigorous development and the detailed technical manuals that accompany the tests. This does not mean that other tests lack reliability or validity, only that information on these tests may be more difficult to obtain. In some cases, the manuals of tests with multiple versions did not contain information on specific topics included in the extraction table when a specific version was being reviewed. In these cases, data from manuals for other editions of the test were used or data were reported that relied on the expert knowledge and judgement of the evaluator, Dr. Roberta White. When data were not available from manuals or other literature (and therefore not reflected in the extraction table), evaluator expert knowledge and judgement were utilized, and such ratings were noted in the evaluation tables.

## Data Availability

Data relevant for evaluating neurodevelopmental tests in epidemiological studies are included in the extraction table available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NIEHS-DATA-NIEHS-01 (NTP 2022).