# Psychometric Tests

## Background

The psychometric outcomes that were evaluated in this document derive from three traditions that have developed over the last 100+ years in the fields of psychology and psychometric assessment. These include the design and evolving development of quantified psychometric tests, the growth of the field of neuropsychological testing, and the exponential increase in neurodevelopmental assessment using psychometric tools in research studies (Lezak 1976).

Throughout this document, these tests are purposely referred to as “neurodevelopmental” and are used in the life-span sense of development/neurodevelopment. While the term “developmental” is often understood to refer to health and functioning in the prenatal and childhood periods, changes in brain structure, function, and organization begin at conception and continue across the life span. Thus, this document uses a life-span developmental psychology approach to characterize brain health and function from conception through death. Indeed, this approach aligns with the approach adopted by many epidemiological studies that were established to study the effect of early life neurotoxicant exposures on neurodevelopment from infancy through childhood and adolescence and into adulthood. Thus, tests are included and discussed in this document that assess adult function, as the administration of childhood tests would be inappropriate at older ages. This approach is consistent with the principle that very early exposures can affect brain structure, organization, and function across the life span and possibly in different ways at different points in the life span.

Psychometric test development began in the early 20th century when psychologists introduced the theory of g or general intelligence, a term for an individual’s overall level of cognitive skills that affects their intellectual functioning. Early tests from Piaget, Binet, and Wechsler were developed to measure g. Although primitive compared with the sophisticated tests used contemporaneously, they included many features still used in contemporaneous tests, including several subtests; standardized instructions and test materials; scoring rules, and basic norms allowing for comparisons of performance among examinees of the same age, including child and adult populations. These tests (especially Stanford-Binet and Wechsler) gave rise to the concept of IQ as an entity, generally quantified as a standard score of 100 as average, with a standard deviation (SD) of 15 or 16, depending on the test. It should be noted that such scores are not meant to serve as the sole measures of an individual’s aptitude or potential for future success given that they are influenced by a variety of factors (Spreen and Strauss 1991). Systematic differences in test performance may exist if individuals come from a population that is distinct from the test’s target population or population used to design the test in terms of race/ethnicity, culture, socioeconomic status, etc. Thus, the scores are a kind of benchmark but are not a concrete entity.

Tests of academic achievement (reading, writing, mathematical skills) also began to appear in the educational psychology literature as school psychologists and personnel required means of assessing whether students were progressing at the expected rate in academic knowledge for age and grade level. These tests also grew in sophistication and became standardized over time.

Other tests that attempted to assess child development/neurodevelopment also began to appear that would allow pediatricians and other clinicians to determine if a child was on a normal neurodevelopmental trajectory or was behind or ahead for his/her age. Tests were also developed to determine if children had typical patterns of cognitive, behavioral, emotional, social, psychiatric, or personality traits (Spreen and Strauss 1991).

Around the mid-20th century, the field of clinical neuropsychology emerged and grew dramatically for several decades. In this field, psychometric tests are used to assess brain function to determine if it is normal or abnormal. If abnormalities are noted, the neuropsychologist may opine on the specific brain structures or systems that are dysfunctional or their likely neurological cause. It had been known since the 1800s that some parts of the brain were responsible for specific kinds of behavior. Discoveries of these relationships stemmed from brain autopsy findings from symptomatic patients. For example, patients with lesions in certain parts of the frontal lobes developed the inability to speak (expressive aphasia), while patients with lesions in posterior portions of the temporal lobes could speak but could not comprehend the speech of others (receptive aphasia). As more associations between specific brain regions and behavioral and cognitive functions became apparent, the notion of structure-function relationships within the brain became more prominent. An impetus for this field was the absence of neuroimaging techniques that are now available by which clinicians could visualize brain tumors, strokes, and other kinds of lesions related to neurological illnesses (e.g., multiple sclerosis plaques, effects of traumatic brain injury). When patients presented to physicians with new acute neurological symptoms, it was important to diagnose how the brain was malfunctioning and which parts of the brain might be affected in order to determine whether a neurosurgical intervention might help or cure the patient (White 1992).

Although neurologists and other clinicians could assess behaviors to try to localize structural damage in the brain, the techniques were generally specific to individual clinicians and not systematically quantified or comparable among clinicians. Individual neuropsychologists and the field of neuropsychology applied standardized psychometric methods to the evaluation of specific aspects of brain function in attempts to determine whether a neurological condition might be present and associated with abnormal test scores, where the lesions/abnormalities in the brain might be located, and possible underlying diagnoses (e.g., dementias, seizure disorders). In fact, neurosurgeons sometimes relied on the lesion location diagnoses of neuropsychologists to treat patients. Some neuropsychologists approached this work by developing new tests designed to assess specific aspects of brain function. For example, the Halstead-Reitan group developed a battery of 10 tests that assessed motor function on both sides of the body, conceptual reasoning skills, working memory, and other skills. Other neuropsychological groups developed their own tests of brain function but also drew from existing psychometric tests that had already been developed, standardized, and normed to determine if these instruments could aid in assessing the functional integrity of the brain and locating lesions in specific brain areas or systems. Thus, the existing IQ tests and their subtests became included in this clinical and research endeavor. As time has passed, an extensive literature has developed describing what these various kinds of tests demonstrate about specific types of brain damage and neurological disorders, validating the tests applied as measures of CNS function and, in fact, as specific indicators of certain kinds of disordered (or functional) brain-behavior relationships. This knowledge continues to evolve given the capacity to “watch” the brain and its systems function as participants undergo tests and carry out behaviors through methods like functional brain imaging (White and Reuben In Press).

Initially, the field of neuropsychology was focused heavily on adults. This probably arose from the greater number of adult patients with neurological disorders. It also could be related, however, to the fact that localized lesions with predictable behavioral anomalies are more common in adults. When a lesion or disorder appears in the developed adult brain, structure-function relationships are well established, and it is often clear where the problem might be. Neurodevelopment is more complicated. During child development, the brain is more plastic with regard to how specific structures mediate behaviors, is capable of compensating when a structure or brain area is diseased (or even absent), can be influenced by acute or chronic exposures during susceptible periods, and develops and expresses behavior in a dynamic fashion given the circumstances occurring at any stage of development. Because of all these considerations, structure-function relationships in early brain development are more diffuse and less “focal” than in adults, and insults to the developing brain—both toxicants and other neurological conditions—may have different effects than would insults on the mature brain. Given these circumstances, neurodevelopmental assessments have used a combination of existing tests for children (e.g., IQ, developmental, academic); adaptations of adult tests for children; and specialized tests that have been developed, standardized, normed, and validated in clinical populations (e.g., Developmental Neuropsychological Assessment, Behavior Assessment System for Children, Child Behavior Checklist, tests that assess clinical conditions in children) (White 2004).

Almost all psychometric tests provide raw scores that can be converted into standard or scaled scores (mean = 10, SD = 3), T-scores (mean = 50, SD = 10), standard scores (mean = 100, SD = 15), and corresponding percentiles using normative or reference data. This practice allows participants’ scores to be compared with one another after removing the effects of age, sex, or other characteristics on each participant’s raw score. For instance, even within narrow age intervals, older children have higher average raw scores on tests of mental and psychomotor development than younger children. By using standard scores, the traits of participants who are different ages (or other characteristics) can be compared. Moreover, an individual’s performance over time can be examined in relation to reference or normative data. Such comparisons between groups or within individuals over time are often made in terms of number of points or in units of SDs away from the average score.

Note that normative data are not required for comparison of scores between individuals when appropriate measures are taken to validly analyze raw scores; however, normative data are necessary and routinely used when making decisions about an individual’s health care, clinical diagnosis, vocational services, education, legal status, etc. In addition, when appropriate normative data are available, they can be used as the outcome in statistical models.

There is a longstanding tension regarding the interpretation of results from population-based studies that examine neurodevelopmental toxicity. Generally, this friction arises from the lack of consensus regarding the “clinical significance” of effects observed in epidemiological studies. In clinical situations, it is appropriate to refer to “abnormalities” or “deficits” in a functional area when an examinee performs poorly on a test (usually 1–2 SDs away from the average score). In epidemiological studies, effect sizes often fall short of being clinically significant in that they occur within the “normal range” of test performance and are typically less than half of an SD away from the average score. However, subtle shifts in a continuous trait can have profound impacts on the tails of a distribution in a population (Needleman 1990; Rose 1985; 2001; Weiss 2000). For instance, a 5-point decrease in a population’s IQ would nearly double the number of people classified as intellectually disabled (Braun 2017). Finally, it is important to refer to subclinical or preclinical findings of lower scores in these situations as “decrements” in performance or “diminished” performance, rather than “deficits” or “impairments” (White and Reuben In Press).

## Test Domains

In the fields of neurodevelopmental psychometric tests and neuropsychology, psychologists often talk about “domains” of behavior. These domains are generally highly functional in nature—that is, they focus on a particular kind of activity such as attention. They are helpful in some ways simply because they allow investigators to group tests into meaningful categories. However, some other issues about the domains are important to consider, which are discussed below.

While these descriptions of neurodevelopment traits are presented as if they are isolated attributes, it is acknowledged that they are dimensional traits that interact with other domains in determining behavior. Indeed, this type of framework (e.g., Research Domain Criteria (https://pubmed.ncbi.nlm.nih.gov/22577302/)) has been adopted by the National Institute of Mental Health to complement the Diagnostic and Statistical Manual approach to characterizing mental health and neurodevelopmental disorders (Morris and Cuthbert 2012).

First, domains roughly map onto the functioning of specific brain regions, but there is generally not a one-to-one correspondence between a domain and a brain region. For instance, while the capacity to pay attention and to monitor or inhibit behaviors is strongly related to functioning of the frontal lobe, other brain regions (e.g., striatum) may also be involved in these behaviors. Similarly, learning and memory functions are mediated by the limbic system, especially the hippocampus and related structures, although other brain structures play a role. Second, many psychometric instruments that are applied in the fields of neurodevelopment, neuropsychological assessment, and developmental neurotoxicity are omnibus tests for which performance is determined by many different kinds of behavioral processes at the same time and do not fit neatly into a functional domain.

Related, some individual tests require highly complex integration of many kinds of functions, and even tests or subtests considered to be domain-focused often rely on several brain regions for successful performance. These kinds of tests may better fit under a category such as “multi-determined tests,” but this is difficult to do because all tests rely on more than one type of ability (i.e., no test is a pure measure of the trait). Interestingly, the tests with many functional demands are often sensitive to an insult such as a neurotoxicant exposure, although they generally do not reveal very much about what portions of the brain the insult has affected. For example, coding tests require respondents to look at a code that pairs symbols with digits and to write in the appropriate digit in a blank space below the symbol according to the code. This task requires an examinee to recognize visual symbols, write quickly and accurately, scan visual arrays quickly, form associations to remember pairs of symbols, inhibit interference from outside stimuli, follow rows and columns, and so on. These multiple determinants of response quality affect the ultimate score—a deficit in any one of them can reduce the score. This is less true of tests that require only paying attention, or writing quickly, or remembering data.

Finally, there are subdomains associated with each domain. For example, “attention” can include the ability to recognize stimuli, capacity to ignore irrelevant stimuli, speed of responding to stimuli, ability to repeat back numbers in order, and so on. Verbal tests can include the ability to provide abstract definitions of vocabulary words, comprehension of spoken language, and/or comprehension of written language. Toxicant-related decrements in performance within each of these subdomains can have different implications for the effects of the exposure on specific structures or systems within the brain during neurodevelopment.

The domains defined here refer to those that were used to evaluate the psychometric outcomes included in the neurodevelopmental research under discussion. Appendix A contains a list of the domains and the tests categorized within each domain (White 2004).

### Omnibus Tests

[underlined: General intelligence/IQ]: Tests measuring general intelligence purport to assess the examinee’s overall level of cognitive or intellectual abilities, usually by applying a variety of types of intellectual challenges.

[underlined: Academic achievement]: Tests in this domain evaluate the child’s ability to carry out academic skills such as reading, spelling, vocabulary, arithmetic, and more complex abilities.

[underlined: Developmental]: These tests assess how successfully an infant or child is acquiring age-appropriate verbal, motor, and social skills.

[underlined: Neuropsychological assessment batteries]: These tests assess a variety of the domain-specific functions described below and may or may not include an overall test score (usually they do not).

### Clinical Assessment Instruments

[underlined: Clinical conditions]: These tests assess a specific diagnostic outcome or set of outcomes (e.g., autism spectrum disorder, attention-deficit disorder, anxiety disorders, neuropsychiatric conditions) to produce a criterion-based clinical diagnosis.

[underlined: Mental status]: Mental status examinations are screening tools used to determine whether an individual’s cognitive function is within expected limits for age.

### Domain-specific Tests

[underlined: Attention]: This domain includes evaluation of capacity to monitor incoming stimuli, inhibit responses to irrelevant stimuli, hold small bits of information for immediate use (“pre-memory”), and listen to instructions and communications. The prefrontal cortex prominently mediates performance on these tasks.

[underlined: Executive function]: Executive function refers to the capacity to manipulate complex stimuli, reason abstractly, develop effective strategies for task completion, and problem solve. It is broadly defined by three subdomains: working memory, cognitive flexibility, and inhibition. Working memory refers to the capacity to hold and simultaneously manipulate information and data from stimuli for task completion. Cognitive flexibility is the ability to adjust behavior in the face of changing demands and goals. Inhibition includes both the ability to ignore irrelevant stimuli or suppress a triggered behavior to sustain efforts to complete a goal. Relevant brain structures include the prefrontal cortex and subcortical white matter connections.

[underlined: Motor function]: Fine motor control, speed, accuracy, and coordination are the key components of motor function. This domain is usually assessed using the hand (manual motor skills). Relevant brain structures that support completion of these tasks include the motor cortex of the frontal lobes, the cerebellum, and the extrapyramidal system (e.g., basal ganglia).

[underlined: Learning and memory]: Learning and memory comprise several processes that include coding visual or verbal information into short-term memory stores, retaining information longer term, recalling newly learned information spontaneously, and recognizing newly learned information that may or may not be recalled spontaneously. Retrograde memory refers to the ability to recall information learned in the more distant past. Brain structures related to learning and memory include the limbic system, specifically the hippocampus, and frontal cortex.

[underlined: Social-emotional]: This domain encompasses expressions of affect or mood (temporary or chronic), including anxiety, depression, and irritability; ability to control strong emotions or reactions to events or people; communication patterns; traits such as tendency to externalize (often associated with attention-deficit/hyperactivity disorder [ADHD] diagnosis) or internalize (often associated with diagnosis of depression); reciprocal social behaviors, repetitive and restricted behaviors (often associated with autism spectrum disorder [ASD]); and personality traits. Relevant brain structures include the prefrontal cortex and limbic system.

[underlined: Verbal/language]: Verbal skills include recognition of word meanings, ability to define vocabulary words abstractly, and comprehension of verbalizations. This domain is sometimes subdivided into verbal and language, with language skills referring more directly to skills associated with aphasia, such as confrontation naming, repetition, simple comprehension, and simple writing and reading. Most aspects of language/verbal function are mediated by the dominant cerebral hemisphere (usually left hemisphere, though aspects of complex interpretation of verbal information and appreciation of verbally expressed humor often involve the nondominant hemisphere).

[underlined: Visuospatial function]: This domain includes the ability to evaluate pictures and drawings with missing details, appreciate and replicate visual designs and drawings, recognize gestalts, detect embedded figures, understand maps and navigate directions, perform facial and abstract design recognition, and complete puzzle and block design assembly. (Tests within this domain sometimes have a significant motor component.) Relevant brain structures include the parietal and occipital lobes, the cerebellum, the extrapyramidal system, and subcortical white matter connections.

[underlined: Processing speed]: Time to complete tasks is assessed by this domain, which in recent years has been added to IQ and other omnibus tests. No parent tests assessing processing speed were identified in the epidemiological studies from the in-progress EPA IRIS toxicological review of MeHg, resulting in no evaluation table for this domain in Appendix B. Subtests belonging to omnibus tests that assess processing speed have been identified and listed for this domain. Relevant brain structures include the frontal and prefrontal cortex, cerebellum and basal ganglia, and the white matter connections within the brain.