# Introduction

This report presents basic principles for reviewing neurodevelopmental tests used in research that assess associations of exposure to known or putative neurotoxic chemicals during neurodevelopment. The emphasis is on the validity and reliability of psychometric tests used to assess neurodevelopment and methodological aspects of administering and interpreting them in epidemiological studies. Psychometric tests are used extensively because they provide a valid and noninvasive means to quantitatively assess brain function or dysfunction. Referenced throughout the document are psychometric tests designed to assess specific neurodevelopmental traits, and the scores obtained from these tests, which are used to quantify and compare the quality of performance on tests that assess these neurodevelopmental traits in and across individuals or populations.

The impetus for these principles and this document grew out of the need for assistance in assessing the quality of and potential biases in these tests when applying systematic review methodology to pediatric environmental epidemiology literature. Specifically for this document, this was done to aid in the development of the in-process U.S. Environmental Protection Agency (EPA) Integrated Risk Information System (IRIS) toxicological review of methylmercury (MeHg). To develop these principles, an evaluation was conducted on psychometric tests used to estimate the effects of MeHg on neurodevelopmental outcomes (see Process of Selecting Tests section). MeHg was a model toxicant to develop this document and associated principles because the developmental neurotoxicity of MeHg has been extensively studied for over 50 years in cohorts around the world, and the literature evaluating neurodevelopmental effects of MeHg captures many representative psychometric tests used in epidemiological research on many other neurotoxicants.

The work described here is important because it recognizes the challenges involved in conducting and reviewing population-based studies of neurodevelopmental toxicity due to a wide array of neurodevelopmental outcomes, the differing psychometric properties of available tests, and the variations in methods used to administer, score, and interpret test results in individual studies. To address this challenge, it is essential to understand the role that psychometric tests play in assessing neurodevelopment, the validity and reliability of these tests, and the least biased methods to administer, score, and interpret psychometric tests.

While some sub-disciplines of epidemiology, such as molecular epidemiology, have similar principles or “best practices” to maintain high validity and reliability by conducting external and internal quality assurance and quality control procedures (e.g., duplicate measurements, standard calibration materials, and interlaboratory proficiency programs) (Gallo et al. 2011), this document is not intended to serve as a set of best practices for the administration of psychometric tests when studying developmental neurotoxicants. Rather, its goal is to provide the necessary background information for understanding psychometric principles and how psychometric tests can be validly and reliability developed, evaluated, and employed when studying neurotoxicity in epidemiological studies. Ultimately, the principles proposed here are designed to assist in systematic reviews of epidemiological studies of potentially neurotoxic chemical exposures and aid in the design of future research studies.

This document is organized as follows. The first section (Psychometric Tests) provides background on psychometric tests and neurodevelopment. The second section (Methodology for Identifying Psychometric Tests and Extracting Test Information) describes the methods for identifying and selecting psychometric tests and extracting information on psychometric features of the selected tests. Then, the principles discussed in this document are presented in two main parts. In Part 1 (Principles for Evaluating Psychometric Tests), the neurodevelopmental domains and the instruments that have been used to assess neurodevelopment in MeHg research are described. Psychometric features, strengths, and weaknesses of these instruments are assessed with the goal of providing information that can be used to determine if an instrument is more or less suitable for addressing a research question of interest. In Part 2 (“Potential Sources of Bias Related to Selection and Administration of Neurodevelopment Assessments in Epidemiological Studies”), principles related to the application of psychometric tests are described along with potential sources of bias related to using the tests to assess neurodevelopment in epidemiological research.