# Conflict of Interest

Individuals identified as authors in the About This Report section have certified that they have no known real or apparent conflict of interest related to neurodevelopmental tests in epidemiological studies.