# Acknowledgments

This work was supported by the Intramural Research Program (ES103316, ES103318, and ES103319) at the National Institute of Environmental Health Sciences (NIEHS), National Institutes of Health and performed for NIEHS under contracts GS00Q14OADU417 (Order No. HHSN273201600015U) and HHSN271201800012I.