# Appendix D Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NIEHS-DATA-NIEHS-01.

## D.1.1 DNT Test Information Extraction Database

DNT Test Information Extraction Database