# Appendix C References for DNT Test Information Extraction Database

For the DNT Test Information Extraction Database, see Appendix D.

## C.1 Test Manuals and Textbooks

Bayley N. 1993. Bayley Scales of Infant Development, 2nd ed: Manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace & Company.

Bender L. 1938. A visual motor gestalt test and its clinical use. Research Monographs No 3. New York, NY: The American Orthopsychiatric Association.

Brannigan GG, Decker SL. 2003. Bender Visual-Motor Gestalt Test, 2nd ed: Examiner's manual. Itasca, IL: Riverside Publishing.

Conners CK. 2001. Conners' Rating Scales - revised: Technical manual. North Tonawanda, NY: Multi-Health Systems, Inc.

Conners CK. 2004. Conners' Continuous Performance Test (CPT II): Version 5 for Windows: Technical guidance and software manual. North Tonawanda, NY: Multi-Health Systems, Inc.

Delis DC, Kramer JH, Kaplan E, Ober BA. 1987. California Verbal Learning Test, research edition: Manual, Version 1. San Antonio, TX: The Psychological Corporation, Harcourt Brace & Company.

Dunn LM, Dunn LM. 1981. Peabody Picture Vocabulary Test - revised: Manual for forms L and M. Circle Pines, MN: American Guidance Service.

Heaton RK, Chelune GJ, Talley JL, Kay GG, Curtiss G. 1993. Wisconsin Card Sorting Test manual: Revised and explained. Psychological Assessment Resources, Inc.

Korkman M, Kirk U, Kemp S. 1998. A developmental neuropsychological assessment: Manual. The Psychological Corporation.

Lezak MD. 1976. Neuropsychological assessment. New York, NY: Oxford University Press, Inc.

Lezak MD. 1995. Neuropsychological assessment, 3rd ed. New York, NY: Oxford University Press.

Lezak MD, Howieson DB, Bigler ED, Tranel D. 2012. Neuropsychological assessment, 5th ed. New York, NY: Oxford University Press.

Lezak MD, Howieson DB, Loring DW, Hannay HJ, Fischer JS. 2004. Neuropsychological assessment, 4th ed. New York, NY: Oxford University Press.

Mather N, Woodcock RW. 2001. Woodcock-Johnson III: Examiner's manual. Itasca, IL: Riverside Publishing.

McCarthy D. 1972. Manual for the McCarthy Scales of Children's Abilities. The Psychological Corporation, Harcourt Brace Jovanovich, Inc.

McGrew KS, Woodcock RW. 2001. Woodcock-Johnson III: Technical manual. Itasca, IL: Riverside Publishing.

McNair DM, Lorr M, Droppleman LF, Heuchert JP. 2005. Profile of mood states technical update: Manual. North Tonawanda, NY: Multi-Health Systems, Inc.

Raven JC. 1956. Guide to using the Coloured Progressive Matrices: Sets A, Ab, B (revised order, 1956). London, England: H.K. Lewis & Co. Ltd.

Raven JC. 1977. Manual for Raven's Progressive Matrices and Vocabular Scales - section 3: Standard progressive matrices. London, England: H.K. Lewis & Co. Ltd.

Roid GH. 2003. Stanford-Binet Intelligence Scales, 5th ed: Examiner's manual. Itasca, IL: Riverside Publisher.

Roid GH. 2003. Stanford-Binet Intelligence Scales, 5th ed: Technical manual. Itasca, IL: Riverside Publisher.

Sattler JM. 2001. Assessment of children: Cognitive applications, 4th ed. San Diego, CA: Jerome M. Sattler, Inc.

Spreen O, Strauss E. 1991. A compendium of neuropsychological tests: Administration, norms, and commentary, 1st ed. New York, NY: Oxford University Press.

Spreen O, Strauss E. 1998. A compendium of neuropsychological tests: Administration, norms, and commentary, 2nd ed. New York, NY: Oxford University Press.

Strauss E, Sherman EMS, Spreen O. 2006. A compendium of neuropsychological tests: Administration, norms, and commentary, 3rd ed. New York, NY: Oxford University Press.

Thorndike RL, Hagen EP, Sattler JM. 1986. Stanford-Binet Intelligence Scales, 4th ed: Guide for administration and scoring. Chicago, IL: The Riverside Publishing Company.

Thorndike RL, Hagen EP, Sattler JM. 1986. Stanford-Binet Intelligence Scales, 4th ed: Technical manual. Chicago, IL: The Riverside Publishing Company.

Wechsler D. 1981. WAIS-R manual: Wechsler Adult Intelligence Scale - revised. San Antonio, TX: The Psychological Corporation.

Wechsler D. 1987. Manual for the Wechsler Intelligence Scale for Children - revised. New York, NY: The Psychological Corporation.

Wechsler D. 1987. Wechsler Memory Scale - 3rd ed: Administration and scoring manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace & Company.

Wechsler D. 1987. Wechsler Memory Scale - revised: Manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace Jovanovich, Inc.

Wechsler D. 1989. Wechsler Preschool and Primary Scale of Intelligence - revised: Manual. New York, NY: The Psychological Corporation, Harcourt Brace Jovanovich, Inc.

Wechsler D. 1991. Wechsler Intelligence Scale for Children - 3rd ed: Manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace Jovanovich, Inc.

Wechsler D. 1997. Wechsler Adult Intelligence Scale - 3rd ed (WAIS-III), Wechsler Memory Scale - 3rd ed (WMS-III): Technical manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace & Company.

Wechsler D. 1997. Wechsler Adult Intelligence Scale - 3rd ed (WAIS-III): Administration and scoring manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace & Company.

Wechsler D. 2003. Wechsler Intelligence Scale for Children - 4th ed: Administration and scoring manual. San Antonio, TX: PsychCorp by Harcourt Assessment, Inc.

Williams KT, Wang JJ. 1997. Technical references to the Peabody Picture Vocabulary Test - 3rd ed (PPVT-III). Circle Pines, MN: American Guidance Service.

Woodcock RW, Johnson MB. 1989. Woodcock-Johnson Psycho-Educational Battery - revised: Tests of cognitive ability: Standard and supplemental batteries. Allen, TX: DLM Teaching Resources.

Woodcock RW, Johnson MB. 1990. Woodcock-Johnson Psycho-Educational Battery - revised: Tests of achievement: Standard and supplemental batteries. The Riverside Publishing Company.

Zimmerman IL, Steiner VG, Pond RE. 1992. Preschool Language Scale-3: Examiner's manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace Jovanovich, Inc.

## C.2 Peer-reviewed Literature

Ahsan S, Murphy G, Kealy S, Sharif F. 2008. Current developmental surveillance: Is it time for change? Ir Med J. 101(4):110-112.

Akaragian S, Dewa C. 1992. Standardization of the Denver Developmental Screening Test for Armenian children. J Pediatr Nurs. 7(2):106-109.

Albers CA, Grieve AJ. 2007. Test review: Bayley, N. (2006). “Bayley Scales of Infant and Toddler Development--3rd ed”. San Antonio, TX--Harcourt Assessment. J Psychoeduc Assess. 25(2):180-190.

Aleksandrowicz MK, Aleksandrowicz DR. 1976. Precursors of ego in neonates: Factor analysis of Brazelton scale data. J Am Acad Child Psychiatry. 15(2):257-268. https://dx.doi.org/10.1016/S0002-7138(09)61486-2

Allen CW, Silove N, Williams K, Hutchins P. 2007. Validity of the social communication questionnaire in assessing risk of autism in preschool children with developmental problems. J Autism Dev Disord. 37(7):1272-1278. https://dx.doi.org/10.1007/s10803-006-0279-7

Allison C, Williams J, Scott F, Stott C, Bolton P, Baron-Cohen S, Brayne C. 2007. The Childhood Asperger Syndrome Test (CAST): Test-retest reliability in a high scoring sample. Autism. 11(2):173-185. https://dx.doi.org/10.1177/1362361307075710

Amod Z, Cockcroft K, Soellaart B. 2007. Use of the 1996 Griffiths Mental Development Scales for infants: A pilot study with a Black, South African sample. J Child Adolesc Ment Health. 19(2):123-130. https://dx.doi.org/10.2989/17280580709486647

Anderko L, Braun J, Auinger P. 2010. Contribution of tobacco smoke exposure to learning disabilities. J Obstet Gynecol Neonatal Nurs. 39(1):111-117. https://dx.doi.org/10.1111/j.1552-6909.2009.01093.x

Anderson PJ, Burnett A. 2017. Assessing developmental delay in early childhood — Concerns with the Bayley-III scales. Clin Neuropsychol. 31(2):371-381. https://dx.doi.org/10.1080/13854046.2016.1216518

Andersson HW. 1996. The Fagan Test of Infant Intelligence: Predictive validity in a random sample. Psychol Rep. 78(3):1015. https://dx.doi.org/10.2466/pr0.1996.78.3.1015

Aoki S, Hashimoto K, Ikeda N, Takekoh M, Fujiwara T, Morisaki N, Mezawa H, Tachibana Y, Ohya Y. 2016. Comparison of the Kyoto Scale of Psychological Development 2001 with the parent-rated Kinder Infant Development Scale (KIDS). Brain Dev. 38(5):481-490. https://dx.doi.org/10.1016/j.braindev.2015.11.001

Arcia E, Ornstein PA, Otto DA. 1991. Neurobehavioral Evaluation System (NES) and school performance. J Sch Psychol. 29(4):337-352. https://dx.doi.org/10.1016/0022-4405(91)90021-I

Arcia E, Otto DA. 1992. Reliability of selected tests from the Neurobehavioral Evaluation System. Neurotoxicol Teratol. 14(2):103-110. https://dx.doi.org/10.1016/0892-0362(92)90058-I

Armstrong K, Iarocci G. 2013. Brief report: The autism spectrum quotient has convergent validity with the social responsiveness scale in a high-functioning sample. J Autism Dev Disord. 43(9):2228-2232. https://dx.doi.org/10.1007/s10803-013-1769-z

Asghar A, Malik TA. 2016. Factor analytic structure and cross-informant agreement for Childhood Disruptive Behaviour Scale. PJPR. 31(1):77-92.

Aylward GP, Verhulst SJ, Colliver JA. 1985. Development of a brief infant neurobehavioral optimality scale: Longitudinal sensitivity and specificity. Dev Neuropsychol. 1(3):265-276. https://dx.doi.org/10.1080/87565648509540313

Baker EL. 1985. A computer-based neurobehavioral evaluation system for occupational and environmental epidemiology: Methodology and validation studies. Neurobehav Toxicol Teratol. 7(4):369-377.

Ball RS. 1977. The Gesell developmental schedules: Arnold Gesell (1880–1961). J Abnorm Child Psychol. 5(3):233-239. https://dx.doi.org/10.1007/BF00913694

Barnard‐Brak L, Brewer A, Chesnut S, Richman D, Schaeffer AM. 2016. The sensitivity and specificity of the Social Communication Questionnaire for autism spectrum with respect to age. Autism Res. 9(8):838-845. https://dx.doi.org/10.1002/aur.1584

Baron-Cohen S, Hoekstra RA, Knickmeyer R, Wheelwright S. 2006. The Autism-Spectrum Quotient (AQ): Adolescent version. J Autism Dev Disord. 36(3):343-350. https://dx.doi.org/10.1007/s10803-006-0073-6

Baron-Cohen S, Wheelwright S, Skinner R, Martin J, Clubley E. 2001. The Autism-Spectrum Quotient (AQ): Evidence from Asperger syndrome/high-functioning autism, males and females, scientists and mathematicians. J Autism Dev Disord. 31(1):5-17. https://dx.doi.org/10.1023/A:1005653411471

Becker PT, Lederman RP, Lederman E. 1989. Neonatal measures of attention and early cognitive status. Res Nurs Health. 12(6):381-388. https://dx.doi.org/10.1002/nur.4770120608

Benasich AA, Bejar, II. 1992. The Fagan Test of Infant Intelligence: A critical review. J Appl Dev Psychol. 13(2):153-171. https://dx.doi.org/10.1016/0193-3973(92)90027-F

Bishop DVM. 1998. Development of the Children's Communication Checklist (CCC): A method for assessing qualitative aspects of communicative impairment in children. J Child Psychol Psychiatr. 39(6):879-891. https://dx.doi.org/10.1017/S0021963098002832

Bishop DVM, Baird G. 2001. Parent and teacher report of pragmatic aspects of communication: Use of the Children's Communication Checklist in a clinical setting. Dev Med Child Neurol. 43(12):809-818. https://dx.doi.org/10.1017/S0012162201001475

Bishop S, Seltzer M. 2012. Self-reported autism symptoms in adults with autism spectrum disorders. J Autism Dev Disord. 42(11):2354-2363. https://dx.doi.org/10.1007/s10803-012-1483-2

Bode MM, D'Eugenio DB, Mettelman BB, Gross SJ. 2014. Predictive validity of the Bayley, 3rd ed at 2 years for intelligence quotient at 4 years in preterm infants. J Dev Behav Pediatr. 35(9):570-575.

Boer F, Westenberg PM. 1994. The factor structure of the Buss and Plomin EAS Temperature Survey (parental ratings) in a Dutch sample of elementary school children. J Pers Assess. 62(3):537. https://dx.doi.org/10.1207/s15327752jpa6203_13

Bölte S, Tomalski P, Marschik PB, Berggren S, Norberg J, Falck-Ytter T, Pokorska O, Jones EJH, Charman T, Roeyers H et al. 2018. Challenges and inequalities of opportunities in European psychiatry research: The example of psychodiagnostic tool availability in research on early autism identification. Eur J Psychol Assess. 34(4):270-277. https://dx.doi.org/10.1027/1015-5759/a000340

Borowitz KC, Glascoe FP. 1986. Sensitivity of the Denver Developmental Screening Test in speech and language screening. Pediatrics. 78(6):1075-1078.

Bos AF, Martijn A, Okken A, Prechtl HFR. 1998. Quality of general movements in preterm infants with transient periventricular echodensities. Acta Paediatr. 87(3):328-335. https://dx.doi.org/10.1111/j.1651-2227.1998.tb01447.x

Botting N. 2004. Children's Communication Checklist (CCC) scores in 11-year-old children with communication impairments. Int J Lang Commun Disord. 39(2):215-227. https://dx.doi.org/10.1080/13682820310001617001

Bould H, Joinson C, Sterne J, Araya R. 2013. The Emotionality Activity Sociability Temperament Survey: Factor analysis and temporal stability in a longitudinal cohort. Pers Individ Dif. 54(5):628-633. https://dx.doi.org/10.1016/j.paid.2012.11.010

Bourdon KH, Goodman R, Rae DS, Simpson G, Koretz DS. 2005. The Strengths and Difficulties Questionnaire: U.S. normative data and psychometric properties. J Am Acad Child Adolesc Psychiatry. 44(6):557. https://dx.doi.org/10.1097/01.chi.0000159157.57075.c8

Bricker D, Squires J. 1989. The effectiveness of parental screening of at-risk infants: The infant monitoring questionnaires. Topics Early Child Spec Educ. 9(3):67-85. https://dx.doi.org/10.1177/027112148900900306

Brown HR, Harvey EA. 2019. Psychometric properties of ADHD symptoms in toddlers. J Clin Child Adolesc Psychol. 48(3):423-439. https://dx.doi.org/10.1080/15374416.2018.1485105

Brown T. 2019. Structural validity of the Bruininks-Oseretsky test of motor proficiency—2nd ed brief form (BOT-2-BF). Res Dev Disabil. 85:92-103. https://dx.doi.org/10.1016/j.ridd.2018.11.010

Brown T, Lalor A. 2009. The Movement Assessment Battery for Children--2nd ed (MABC-2): A review and critique. Phys Occup Ther Pediatr. 29(1):86-103.

Brugha TS, McManus S, Smith J, Scott FJ, Meltzer H, Purdon S, Berney T, Tantam D, Robinson J, Radley J et al. 2012. Validating two survey methods for identifying cases of autism spectrum disorder among adults in the community. Psychol Med. 42(3):647-656. https://dx.doi.org/10.1017/S0033291711001292

Burakevych N, McKinlay CJD, Alsweiler JM, Wouldes TA, Harding JE. 2017. Bayley-III motor scale and neurological examination at 2 years do not predict motor skills at 45 years. Dev Med Child Neurol. 59(2):216-223. https://dx.doi.org/10.1111/dmcn.13232

Buss AH, Plomin R. 1984. Temperament: Early developing personality traits. Hillsdale, NJ: Lawrence Erlbaum Associates.

Campbell JM. 2005. Diagnostic assessment of Asperger's disorder: A review of five third-party rating scales. J Autism Dev Disord. 35(1):25-35. https://dx.doi.org/10.1007/s10803-004-1028-4

Chandler S, Charman T, Baird G, Simonoff E, Loucas T, Meldrum D, Scott M, Pickles A. 2007. Validation of the social communication questionnaire in a population cohort of children with autism spectrum disorders. J Am Acad Child Adolesc Psychiatry. 46(10):1324-1332. https://dx.doi.org/10.1097/chi.0b013e31812f7d8d

Chesnut SR, Wei T, Barnard-Brak L, Richman DM. 2017. A meta-analysis of the social communication questionnaire: Screening for autism spectrum disorder. Autism. 21(8):920-928. https://dx.doi.org/10.1177/1362361316660065

Chorpita BF, Yim L, Moffitt C, Umemoto LA, Francis SE. 2000. Assessment of symptoms of DSM-IV anxiety and depression in children: A revised child anxiety and depression scale. Behav Res Ther. 38(8):835-855. https://dx.doi.org/10.1016/S0005-7967(99)00130-8

Chow SMK, Chan L, Chan CPS, Lau CHY. 2002. Reliability of the experimental version of the Movement ABC. Br J Ther Rehab. 9(10):404-407. https://dx.doi.org/10.12968/bjtr.2002.9.10.13677

Chow SMK, Henderson SE. 2003. Interrater and test-retest reliability of the Movement Assessment Battery for Chinese preschool children. Am J Occup Ther. 57(5):574-577. https://dx.doi.org/10.5014/ajot.57.5.574

Chwen-Jen C, Li C, Li-Yin C. 2003. Developmental status among 3 to 5-Year-Old preschool children in three kindergartens in the Peitou District of Taipei City. J Nurs Res. 11(2):73.

Cirelli I, Graz MB, Tolsa JF. 2015. Comparison of Griffiths-II and Bayley-II tests for the developmental assessment of high-risk infants. Infant Behav Dev. 41:17-25. https://dx.doi.org/10.1016/j.infbeh.2015.06.004

Cohen LG. 1993. Wechsler Individual Achievement Test. Diagnostique. 18(3):255-268. https://dx.doi.org/10.1177/153450849301800306

Costa R, Figueiredo B, Tendais I, Conde A, Pacheco A, Teixeira C. 2010. Brazelton Neonatal Behavioral Assessment Scale: A psychometric study in a Portuguese sample. Infant Behav Dev. 33(4):510-517. https://dx.doi.org/10.1016/j.infbeh.2010.07.003

Croce RV, Horvat M, McCarthy E. 2001. Reliability and concurrent validity of the movement assessment battery for children. Percept Mot Skills. 93(1):275. https://dx.doi.org/10.2466/pms.2001.93.1.275

Darsaklis V, Snider LM, Majnemer A, Mazer B. 2011. Predictive validity of Prechtl's Method on the Qualitative Assessment of General Movements: A systematic review of the evidence. Dev Med Child Neurol. 53(10):896-906. https://dx.doi.org/10.1111/j.1469-8749.2011.04017.x

de la Osa N, Granero R, Penelo E, Ezpeleta L. 2014. Usefulness of the Social and Communication Disorders Checklist (SCDC) for the assessment of social cognition in preschoolers. Eur J Psychol Assess. 30(4):296-303. https://dx.doi.org/10.1027/1015-5759/a000193

De Pauw SSW, Mervielde I, Van Leeuwen KG. 2009. How are traits related to problem behavior in preschoolers? Similarities and contrasts between temperament and personality. J Abnorm Child Psychol. 37(3):309-325. https://dx.doi.org/10.1007/s10802-008-9290-0

De-Andrés-Beltrán B, Rodríguez-Fernández AL, Güeita-Rodríguez J, Lambeck J, Rodríguez-Fernández Á. 2015. Evaluation of the psychometric properties of the Spanish version of the Denver Developmental Screening Test II. Eur J Pediatr. 174(3):325-329. https://dx.doi.org/10.1007/s00431-014-2410-7

Douglas A, Letts L, Liu L. 2008. Review of cognitive assessments for older adults. Phys Occup Ther Geriatr. 26(4):13-43. https://dx.doi.org/10.1080/02703180801963758

Eaves RC, Milner B. 1993. The criterion-related validity of the Childhood Autism Rating Scale and the Autism Behavior Checklist. J Abnorm Child Psychol. 21:481-491. https://dx.doi.org/10.1007/BF00916315

Einspieler C, Bos AF, Libertus ME, Marschik PB. 2016. The general movement assessment helps us to identify preterm infants at risk for cognitive dysfunction. Front Psychol. 7. https://dx.doi.org/10.3389/fpsyg.2016.00406

Einspieler C, Prechtl HFR. 2005. Prechtl's assessment of general movements: A diagnostic tool for the functional assessment of the young nervous system. Ment Retard Dev Disabil Res Rev. 11(1):61-67. https://dx.doi.org/10.1002/mrdd.20051

Einspieler C, Yang H, Bartl-Pokorny KD, Chi X, Zang FF, Marschik PB, Guzzetta A, Ferrari F, Bos AF, Cioni G. 2015. Are sporadic fidgety movements as clinically relevant as is their absence? Early Hum Dev. 91(4):247-252. https://dx.doi.org/10.1016/j.earlhumdev.2015.02.003

Essau CA, Anastassiou-Hadjicharalambous X, Muñoz LC. 2011. Psychometric properties of the Spence Children's Anxiety Scale (SCAS) in Cypriot children and adolescents. Child Psychiatry Hum Dev. 42(5):557-568. https://dx.doi.org/10.1007/s10578-011-0232-7

Essau CA, Muris P, Ederer EM. 2002. Reliability and validity of the Spence Children's Anxiety Scale and the Screen for Child Anxiety Related Emotional Disorders in German children. J Behav Ther Exp Psychiatry. 33(1):1-18. https://dx.doi.org/10.1016/S0005-7916(02)00005-8

Fagan JF, Detterman DK. 1992. The Fagan Test of Infant Intelligence: A technical summary. J Appl Dev Psychol. 13(2):173-193. https://dx.doi.org/10.1016/0193-3973(92)90028-G

Fagan JF, Shepard P. 1986. The Fagan test of infant intelligence. Cleveland, OH: Infantest Corporation. 87.

Field TM, Hallock NF, Dempsey JR, Shuman HH. 1978. Mothers' assessments of term and pre-term infants with respiratory distress syndrome: Reliability and predictive validity. Child Psychiatry Hum Dev. 9(2):75-85. https://dx.doi.org/10.1007/BF01448351

Foreman MD. 1987. Reliability and validity of mental status questionnaires in elderly hospitalized patients... the SPMSQ, MMSE, and CCSE. Nurs Res. 36(4):216-220. https://dx.doi.org/10.1097/00006199-198707000-00004

Frankenburg WK, Camp BW, van Natta PA. 1971. Validity of the Denver Developmental Screening Test. Child Dev. 42(2):475-485. https://dx.doi.org/10.2307/1127481

Frankenburg WK, Dodds J, Archer P, Shapiro H, Bresnick B. 1992. The Denver II: A major revision and restandardization of the Denver Developmental Screening Test. Pediatrics. 89(1):91.

Frankenburg WK, Dodds JB. 1967. The Denver Developmental Screening Test. J Pediatr. 71(2):181-191. https://dx.doi.org/10.1016/S0022-3476(67)80070-2

Frankenburg WK, Fandal AW, Thornton SM. 1987. Revision of Denver Prescreening Developmental Questionnaire. J Pediatr. 110(4):653-657. https://dx.doi.org/10.1016/S0022-3476(87)80573-5

Friend TJ, Channell RW. 1987. A comparison of two measures of receptive vocabulary. Lang Speech Hear Serv Sch. 18(3):231-237. https://dx.doi.org/10.1044/0161-1461.1803.231

Gage GE, Naumann TF. 1965. Correlation of the Peabody Picture Vocabulary Test and the Wechsler Intelligence Scale for Children. J Educ Res. 58(10):466-468. https://dx.doi.org/10.1080/00220671.1965.10883277

Galeote M, Checa E, Sánchez-Palacios C, Sebastián E, Soto P. 2016. Adaptation of the MacArthur-Bates Communicative Development Inventories for Spanish children with Down syndrome: Validity and reliability data for vocabulary. Am J Speech Lang Pathol. 25(3):1-10. https://dx.doi.org/10.1044/2015_AJSLP-15-0007

Gard L, Rosblad B. 2009. The qualitative motor observations in Movement ABC: Aspects of reliability and validity. Adv Physiother. 11(2):51-57. https://dx.doi.org/10.1080/14038190902792346

Gau S-F, Lee CF, Lai MC, Chiu YN, Huang YF, Kao JD, Wu YY. 2011. Psychometric properties of the Chinese version of the Social Communication Questionnaire. Res Autism Spectr Disord. 5(2):809-818. https://dx.doi.org/10.1016/j.rasd.2010.09.010

Geurts H, Hartman C, Verte S, Oosterlaan J, Roeyers H, Sergeant J. 2009. Pragmatics fragmented: The factor structure of the Dutch Children's Communication Checklist (CCC). Int J Lang Commun Disord. 44(5):549-574. https://dx.doi.org/10.1080/13682820802243344

Gill K, Osiovich A, Synnes A, Agnew JA, Grunau RE, Miller SP, Zwicker JG. 2019. Concurrent validity of the Bayley-III and the Peabody Developmental Motor Scales-2 at 18 months. Phys Occup Ther Pediatr. 39(5):514-524. https://dx.doi.org/10.1080/01942638.2018.1546255

Glascoe FP, Byrne KE. 1993. The accuracy of three developmental screening tests. J Early Interv. 17(4):368-379. https://dx.doi.org/10.1177/105381519301700403

Glutting JJ, Youngstrom EA, Ward T. 1997. Incremental efficacy of WISC-III factor scores in predicting achievement: What do they tell us? Psychol Assess. 9:295-301. https://dx.doi.org/10.1037/1040-3590.9.3.295

Goodman R. 2001. Psychometric properties of the Strengths and Difficulties Questionnaire. J Am Acad Child Adolesc Psychiatry. 40(11):1337. https://dx.doi.org/10.1097/00004583-200111000-00015

Gratz KL, Roemer L. 2004. Multidimensional assessment of emotion regulation and dysregulation: Development, factor structure, and initial validation of the Difficulties in Emotion Regulation Scale. J Psychopathol Behav Assess. 26(1):41-54. https://dx.doi.org/10.1023/B:JOBA.0000007455.08539.94

Greer S, Bauchner H, Zuckerman B. 1989. The Denver Developmental Screening Test: How good is its predictive validity? Dev Med Child Neurol. 31(6):774-781. https://dx.doi.org/10.1111/j.1469-8749.1989.tb04073.x

Griffiths A, Morgan P, Anderson PJ, Doyle LW, Lee KJ, Spittle AJ. 2017. Predictive value of the Movement Assessment Battery for Children - 2nd ed at 4 years, for motor impairment at 8 years in children born preterm. Dev Med Child Neurol. 59(5):490-496.

Hadders‐Algra M, Philippi H. 2018. Predictive validity of the General Movements Assessment: Type of population versus type of assessment. Dev Med Child Neurol. 60(11):1186-1186. https://dx.doi.org/10.1111/dmcn.14000

Hadley PA, Rice ML. 1993. Parental judgments of preschoolers' speech and language development: A resource for assessment and IEP planning. Semin Speech Lang. 14(4):278-288. https://dx.doi.org/10.1055/s-2008-1064177

Hattie J, Edwards H. 1987. A review of the Bruininks-Oseretsky Test of Motor Proficiency. Br J Educ Psychol. 57(1):104-113. https://dx.doi.org/10.1111/j.2044-8279.1987.tb03065.x

He J, Qiu P, Park KY, Xu Q, Potegal M. 2013. Young Chinese children’s anger and distress: Emotion category and intensity identified by the time course of behaviors. Int J Behav Dev. 37(4):349-356. https://dx.doi.org/10.1177/0165025413477006

Heilmann J, Weismer SE, Evans J, Hollar C. 2005. Utility of the MacArthur-Bates Communicative Development Inventory in identifying language abilities of late-talking and typically developing toddlers. Am J Speech Lang Pathol. 14(1):40-51. http://dx.doi.org/10.1044/1058-0360(2005/006)

Hoekstra RA, Bartels M, Cath DC, Boomsma DI. 2008. Factor structure, reliability and criterion validity of the Autism-Spectrum Quotient (AQ): A study in Dutch population and patient groups. J Autism Dev Disord. 38(8):1555-1566. https://dx.doi.org/10.1007/s10803-008-0538-x

Hoffman LM, Loeb DF, Brandel J, Gillam RB. 2011. Concurrent and construct validity of oral language measures with school-age children with specific language impairment. J Speech Lang Hear Res. 54(6):1597-1608. http://dx.doi.org/10.1044/1092-4388(2011/10-0213)

Howieson DB, Lezak MD. 2007. Neuropsychological assessment. In: Bourgeois JA, Hales RE, Yudofsky SC, editors. The American Psychiatric Publishing Board Prep and Review Guide for Psychiatry. Arlington, VA: American Psychiatric Publishing, Inc. p. 55-61.

Ishikawa SI, Sato H, Sasagawa S. 2009. Anxiety disorder symptoms in Japanese children and adolescents. J Anxiety Disord. 23(1):104-111. https://dx.doi.org/10.1016/j.janxdis.2008.04.003

Junge C, Cutler A. 2014. Early word recognition and later language skills. Brain Sci. 4(4):532-559. https://dx.doi.org/10.3390/brainsci4040532

Kambas A, Aggeloussis N. 2006. Construct validity of the Bruininks-Oseretsky Test of Motor Proficiency-Short Form for a sample of Greek preschool and primary school children. Percept Mot Skills. 102(1):65-72.

Ketelaars MP, Cuperus JM, van Daal J, Jansonius K, Verhoeven L. 2009. Screening for pragmatic language impairment: The potential of the children's communication checklist. Res Dev Disabil. 30(5):952-960. https://dx.doi.org/10.1016/j.ridd.2009.01.006

Kooijman V, Junge C, Johnson EK, Hagoort P, Cutler A. 2013. Predictive brain signals of linguistic development. Front Psychol. 4. https://dx.doi.org/10.3389/fpsyg.2013.00025

Koyama T, Osada H, Tsujii H, Kurita H. 2009. Utility of the Kyoto Scale of Psychological Development in cognitive assessment of children with pervasive developmental disorders. Psychiatry Clin Neurosci. 63(2):241-243. https://dx.doi.org/10.1111/j.1440-1819.2009.01931.x

Krengel M, White RF, Diamond R, Leeza R. 1996. A comparison of NES2 and traditional neuropsychological tests in a neurologic patient sample. Neurotoxicol Teratol. 18(4):435-439. https://dx.doi.org/10.1016/0892-0362(96)00022-0

Krohn EJ, Traxler AJ. 1979. Relationship of the McCarthy Scales of Children's Abilities to other measures of preschool cognitive, motor, and perceptual development. Percept Mot Skills. 49(3):783-790. https://dx.doi.org/10.2466/pms.1979.49.3.783

Kwong AKL, Fitzgerald TL, Doyle LW, Cheong JLY, Spittle AJ. 2018. Predictive validity of spontaneous early infant movement for later cerebral palsy: A systematic review. Dev Med Child Neurol. 60(5):480-489. https://dx.doi.org/10.1111/dmcn.13697

Lam HMY. 2011. Assessment of preschoolers' gross motor proficiency: Revisiting Bruininks-Oseretsky Test of Motor Proficiency. Early Child Dev Care. 181(2):189-201. https://dx.doi.org/10.1080/03004430.2011.536640

Lester BM, Tronick EZ. 2004. History and description of the Neonatal Intensive Care Unit Network Neurobehavioral Scale. Pediatrics. 113:634-640.

Lim HC, Chan T, Yoong T. 1994. Standardisation and adaptation of the Denver Developmental Screening Test (DDST) and Denver II for use in Singapore children. Singapore Med J. 35(2):156-160.

Littell WM. 1960. The Wechsler Intelligence Scale for Children: Review of a decade of research. Psychol Bull. 57(2):132-156. https://dx.doi.org/10.1037/h0044513

Liu J, Bann C, Lester B, Tronick E, Das A, Lagasse L, Bauer C, Shankaran S, Bada H. 2010. Neonatal neurobehavior predicts medical and behavioral outcome. Pediatrics. 125(1):e90-e98. https://dx.doi.org/10.1542/peds.2009-0204

Loong NKS. 2016. Psychometric characteristics of a Chinese translation of the Barkley Adult ADHD Rating Scale-IV (BAARS-IV) in Hong Kong. [Hong Kong]: Alliant International University.

Lopez B, Lincoln A, Ozonoff S, Lai Z. 2005. Examining the relationship between executive functions and restricted, repetitive symptoms of autistic disorder. J Autism Dev Disord. 35(4):445-460. https://dx.doi.org/10.1007/s10803-005-5035-x

Luiz DM, Foxcroft CD, Povey JL. 2006. The Griffiths Scales of Mental Development: A factorial validity study. South African Journal of Psychology. 36(1):192-214. https://dx.doi.org/10.1177/008124630603600111

Luiz DM, Foxcroft CD, Stewart R. 2001. The construct validity of the Griffiths Scales of Mental Development. Child Care Health Dev. 27(1):73-83. https://dx.doi.org/10.1046/j.1365-2214.2001.00158.x

Luiz DM, Foxcroft CD, Tukulu AN. 2004. The Denver II Scales and the Griffiths Scales of Mental Development: A correlational study. J Child Adolesc Ment Health. 16(2):77-81. https://dx.doi.org/10.2989/17280580409486573

Lynch R. 2018. The psychometric properties of the Barkley Adult ADHD Rating Scale: IV (BAARS-IV) in a college sample. [Tallahassee, FL]: Florida State University.

Magiati I, Lerh JW, Hollocks MJ, Uljarevic M, Rodgers J, McConachie H, Ozsivadjian A, South M, Van Hecke A, Hardan A et al. 2017. The measurement properties of the Spence Children's Anxiety Scale‐Parent Version in a large international pooled sample of young people with autism spectrum disorder. Autism Res. 10(10):1629-1652. https://dx.doi.org/10.1002/aur.1809

Majnemer A, Mazer B. 1998. Neurologic evaluation of the newborn infant: Definition and psychometric properties. Dev Med Child Neurol. 40(10):708-715. https://dx.doi.org/10.1111/j.1469-8749.1998.tb12332.x

Mathiesen KS, Tambs K. 1999. The EAS Temperament Questionnaire--factor structure, age trends, reliability, and stability in a Norwegian sample. J Child Psychol Psychiatry. 40(3):431-439. https://dx.doi.org/10.1111/1469-7610.00460

Meisels SJ. 1989. Can developmental screening tests identify children who are developmentally at risk? Pediatrics. 83(4):578.

Meyer A, Eilertsen DE, Sundet JM, Tshifularo J, Sagvolden T. 2004. Cross-cultural similarities in ADHD-like behaviour amongst South African Primary school children. S Afr J Psychol. 34(1):122-138. https://dx.doi.org/10.1177/008124630403400108

Milne SL, McDonald JL, Comino EJ. 2015. Alternate scoring of the Bayley- III improves prediction of performance on Griffiths Mental Development Scales before school entry in preschoolers with developmental concerns. Child Care Health Dev. 41(2):203-212. https://dx.doi.org/10.1111/cch.12177

Mitsopoulou E, Kafetsios K, Karademas E, Papastefanakis E, Simos P. 2013. The Greek Version of the Difficulties in Emotion Regulation Scale: Testing the factor structure, reliability and validity in an adult community sample. J Psychopathol Behav Assess. 35(1):123-131. https://dx.doi.org/10.1007/s10862-012-9321-6

Molina BS, Pelham WE, Blumenthal J, Galiszewski E. 1998. Agreement among teachers' behavior ratings of adolescents with a childhood history of attention deficit hyperactivity disorder. J Clin Child Psychol. 27(3):330-339. https://dx.doi.org/10.1207/s15374424jccp2703_9

Munsell KL. 2007. A screening battery for identifying at-risk infants: Prediction of outcome on Bayley Scales of Infant/Todder Development-III. [Fresno, CA]: Alliant International.

Muris P, Meesters C, van den Berg F. 2003. The Strengths and Difficulties Questionnaire (SDQ): Further evidence for its reliability and validity in a community sample of Dutch children and adolescents. Eur Child Adolesc Psychiatry. 12(1):1. https://dx.doi.org/10.1007/s00787-003-0298-2

Mutlu A, Livanelioğlu A, Korkmaz A. 2010. Assessment of “general movements” in high-risk infants by Prechtl analysis during early intervention period in the first year of life. Turk J Pediatr. 52(6):630-637.

Newcomer P, Hammill DD. 1978. Using the Test of Language Development with language-impaired children. J Learn Disabil. 11(8):521-524. https://dx.doi.org/10.1177/002221947801100811

Nishiyama T, Suzuki M, Adachi K, Sumi S, Okada K, Kishino H, Sakai S, Kamio Y, Kojima M, Suzuki S et al. 2014. Comprehensive comparison of self-administered questionnaires for measuring quantitative autistic traits in adults. J Autism Dev Disord. 44(5):993-1007. https://dx.doi.org/10.1007/s10803-013-2020-7

Noble Y, Boyd R. 2012. Neonatal assessments for the preterm infant up to 4 months corrected age: A systematic review. Dev Med Child Neurol. 54(2):129-139. https://dx.doi.org/10.1111/j.1469-8749.2010.03903.x

Nordahl-Hansen A, Kaale A, Ulvund SE. 2013. Inter-rater reliability of parent and preschool teacher ratings of language in children with autism. Res Autism Spectr Disord. 7(11):1391-1396. https://dx.doi.org/10.1016/j.rasd.2013.08.006

Nugent JH. 1976. A comment on the efficiency of the revised Denver Developmental Screening Test. Am J Ment Defic. 80(5):570-572.

Owens JS, Storer J, Holdaway AS, Serrano VJ, Watabe Y, Himawan LK, Krelko RE, Vause KJ, Girio-Herrera E, Andrews N. 2015. Screening for social, emotional, and behavioral problems at kindergarten entry: Utility and incremental validity of parent report. School Psych Rev. 44(1):21-40. https://dx.doi.org/10.17105/SPR44-1.21-40

Papay JP, Spielberger CD. 1986. Assessment of anxiety and achievement in kindergarten and first- and second-grade children. J Abnorm Child Psychol. 14(2):279-286. https://dx.doi.org/10.1007/BF00915446

Parmenter BA, Zivadinov R, Kerenyi L, Gavett R, Weinstock-Guttman B, Dwyer MG, Garg N, Munschauer F, Benedict RHB. 2007. Validity of the Wisconsin Card Sorting and Delis–Kaplan Executive Function System (DKEFS) Sorting Tests in multiple sclerosis. J Clin Exp Neuropsychol. 29(2):215-223. https://dx.doi.org/10.1080/13803390600672163

Patterson RL, Osullivan MJ, Spielberger CD. 1980. Measurement of state and trait anxiety in elderly mental health clients. J Behav Assess. 2(2):89-97. https://dx.doi.org/10.1007/BF01338925

Pease D, Rosauer JK, Wolins L. 1961. Reliability of three infant developmental scales administered during the first year of life. J Genet Psychol. 98:295-298. https://dx.doi.org/10.1080/00221325.1961.10534380

Pelletier J, Collett B, Gimpel G, Crowley S. 2006. Assessment of disruptive behaviors in preschoolers: Psychometric properties of the Disruptive Behavior Disorders Rating Scale and School Situations Questionnaire. J Psychoeduc Assess. 24(1):3-18. https://dx.doi.org/10.1177/0734282905285235

Pilowsky T, Yirmiya N, Shulman C, Dover R. 1998. The Autism Diagnostic Interview-Revised and the Childhood Autism Rating Scale: Differences between diagnostic systems and comparison between genders. J Autism Dev Disord. 28(2):143-151. https://dx.doi.org/10.1023/A:1026092632466

Putnam SP, Gartstein MA, Rothbart MK. 2006. Measurement of fine-grained aspects of toddler temperament: The Early Childhood Behavior Questionnaire. Infant Behav Dev. 29(3):386-401. https://dx.doi.org/10.1016/j.infbeh.2006.01.004

Robinson EB, Munir K, Munafo MR, Hughes M, McCormick MC, Koenen KC. 2011. Stability of autistic traits in the general population: Further evidence for a continuum of impairment. J Am Acad Child Adolesc Psychiatry. 50(4):376-384. https://dx.doi.org/10.1016/j.jaac.2011.01.005

Ronald A, Simonoff E, Kuntsi J, Asherson P, Plomin R. 2008. Evidence for overlapping genetic influences on autistic and ADHD behaviours in a community twin sample. J Child Psychol Psychiatr. 49(5):535-542. https://dx.doi.org/10.1111/j.1469-7610.2007.01857.x

Ronald A, Viding E, Happé F, Plomin R. 2006. Individual differences in theory of mind ability in middle childhood and links with verbal ability and autistic traits: A twin study. Soc Neurosci. 1(3):412-425. https://dx.doi.org/10.1080/17470910601068088

Rowe DC, Plomin R. 1977. Temperament in early childhood. J Pers Assess. 41(2):150-156. https://dx.doi.org/10.1207/s15327752jpa4102_5

Rubio-Codina M, Araujo MC, Attanasio O, Muñoz P, Grantham-McGregor S. 2016. Concurrent validity and feasibility of short tests currently used to measure early childhood development in large scale studies. PLoS One. 11(8). https://dx.doi.org/10.1371/journal.pone.0160962

Saemundsen E, Magnusson P, Smari J, Sigurdardottir S. 2003. Autism diagnostic interview-revised and the childhood Autism Rating Scale: Convergence and discrepancy in diagnosing autism. J Autism Dev Disord. 33(3):319. https://dx.doi.org/10.1023/A:1024410702242

Salisbury AL, Fallone MD, Lester B. 2005. Neurobehavioral assessment from fetus to infant: The NICU Network Neurobehavioral Scale and the Fetal Neurobehavior Coding Scale. Ment Retard Dev Disabil Res Rev. 11(1):14-20. https://dx.doi.org/10.1002/mrdd.20058

Sappok T, Brooks W, Heinrich M, McCarthy J, Underwood L. 2017. Cross-cultural validity of the social communication questionnaire for adults with intellectual developmental disorder. J Autism Dev Disord. 47(2):393-404. https://dx.doi.org/10.1007/s10803-016-2967-2

Sappok T, Diefenbacher A, Gaul I, Bölte S. 2015. Validity of the Social Communication Questionnaire in adults with intellectual disabilities and suspected Autism spectrum disorder. Am J Intellect Dev Disabil. 120(3):203-214. https://dx.doi.org/10.1352/1944-7558-120.3.203

Schopler E, Reichler RJ, DeVellis RF, Daly K. 1980. Toward objective classification of childhood autism: Childhood Autism Rating Scale (CARS). J Autism Dev Disord. 10(1):91-103. https://dx.doi.org/10.1007/BF02408436

Scott FJ, Baron-Cohen S, Bolton P, Brayne C. 2002. The CAST (Childhood Asperger Syndrome Test): Preliminary development of a UK screen for mainstream primary-school-age children. Autism. 6(1):9-31. https://dx.doi.org/10.1177/1362361302006001003

Scott FJ, Baron-Cohen S, Bolton P, Brayne C. 2002. 'The CAST (Childhood Asperger Syndrome Test): Preliminary development of a UK screen for mainstream primary-school-age children - Erratum. Autism. 6(4). https://dx.doi.org/10.1177/1362361302006001003

Sevin JA, Matson JL, Coe DA, Fee VE, Sevin BM. 1991. A comparison and evaluation of three commonly used autism scales. J Autism Dev Disord. 21(4):417-432. https://dx.doi.org/10.1007/BF02206868

Skuse DH, Mandy WPL, Scourfield J. 2005. Measuring autistic traits: Heritability, reliability and validity of the Social and Communication Disorders Checklist. Br J Psychiatry. 187:568-572. https://dx.doi.org/10.1192/bjp.187.6.568

Snider LM, Majnemer A, Mazer B, Campbell S, Bos AF. 2008. A comparison of the general movements assessment with traditional approaches to newborn and infant assessment: Concurrent validity. Early Hum Dev. 84(5):297-303. https://dx.doi.org/10.1016/j.earlhumdev.2007.07.004

Spence R, Owens M, Goodyer I. 2013. The longitudinal psychometric properties of the EAS Temperament Survey in adolescence. J Pers Assess. 95(6):633-639. https://dx.doi.org/10.1080/00223891.2013.819513

Spence SH. 1998. A measure of anxiety symptoms among children. Behav Res Ther. 36(5):545-566. https://dx.doi.org/10.1016/S0005-7967(98)00034-5

Spielberger CD. 1985. Assessment of state and trait anxiety: Conceptual and methodological issues. S Psychol. 2(4):6-16.

Spironello C, Hay J, Missiuna C, Faught BE, Cairney J. 2010. Concurrent and construct validation of the short form of the Bruininks-Oseretsky Test of Motor Proficiency and the Movement-ABC when administered under field conditions: Implications for screening. Child Care Health Dev. 36(4):499-507. https://dx.doi.org/10.1111/j.1365-2214.2009.01066.x

Spittle AJ, Doyle LW, Boyd RN. 2008. A systematic review of the clinimetric properties of neuromotor assessments for preterm infants during the first year of life. Dev Med Child Neurol. 50(4):254-266. https://dx.doi.org/10.1111/j.1469-8749.2008.02025.x

Stępień-Nycz M, Rostek I, Białecka-Pikul M, Białek A. 2018. The Polish adaptation of the Early Childhood Behavior Questionnaire (ECBQ): Psychometric properties, age and gender differences and convergence between the questionnaire and the observational data. Eur J Dev Psychol. 15(2):192-213. https://dx.doi.org/10.1080/17405629.2017.1292906

Sullivan MC, Miller RJ, Fontaine LA, Lester B. 2012. Refining neurobehavioral assessment of the high‐risk infant using the NICU Network Neurobehavioral Scale. J Obstet Gynecol Neonatal Nurs. 41(1):17-23.

Takeda T, Burns GL, Jiang Y, Becker SP, McBurnett K. 2019. Psychometric properties of a sluggish cognitive tempo scale in Japanese adults with and without ADHD. Atten Defic Hyperact Disord. 11(4):353-362. https://dx.doi.org/10.1007/s12402-019-00300-z

Tasbihsazan R, Nettelbeck T, Kirby N. 2003. Predictive validity of the Fagan Test of Infant Intelligence. Br J Dev Psychol. 21(4):585-597. https://dx.doi.org/10.1348/026151003322535237

Teal MB, Wiebe MJ. 1986. A validity analysis of selected instruments used to assess autism. J Autism Dev Disord. 16:485-494. https://dx.doi.org/10.1007/BF01531713

Thal D, DesJardin JL, Eisenberg LS. 2007. Validity of the MacArthur–Bates Communicative Development Inventories for measuring language abilities in children with cochlear implants. J Med Speech Lang Pathol. 16(1):54-64. http://dx.doi.org/10.1044/1058-0360(2007/007)

Treloar JM. 1994. Wechsler Individual Achievement Test (WIAT). Interv Sch Clin. 29(4):242. https://dx.doi.org/10.1177/105345129402900409

Tronick E, Lester BM. 2013. Grandchild of the NBAS: The NICU Network Neurobehavioral Scale (NNNS): A review of the research using the NNNS. J Child Adolesc Psychiatr Nurs. 26(3):193-203.

Valentin T, Uhl K, Einspieler C. 2005. The effectiveness of training in Prechtl's method on the qualitative assessment of general movements. Early Hum Dev. 81(7):623-627. https://dx.doi.org/10.1016/j.earlhumdev.2005.04.003

Van Eck K, Finney SJ, Evans SW. 2010. Parent report of ADHD symptoms of early adolescents: A confirmatory factor analysis of the Disruptive Behavior Disorders Scale. Educ Psychol Meas. 70(6):1042-1059. https://dx.doi.org/10.1177/0013164410378093

Vasilev CA, Crowell SE, Beauchaine TP, Mead HK, Gatzke‐Kopp LM. 2009. Correspondence between physiological and self-report measures of emotion dysregulation: A longitudinal investigation of youth with and without psychopathology. J Child Psychol Psychiatr. 50(11):1357-1364. https://dx.doi.org/10.1111/j.1469-7610.2009.02172.x

Vaughn BE, Taraldson B, Crichton L, Egeland B. 1980. Relationships between neonatal behavioral organization and infant behavior during the first year of life. Infant Behav Dev. 3(1):47-66. https://dx.doi.org/10.1016/S0163-6383(80)80006-3

Venetsanou F, Kambas A, Aggeloussis N, Fatouros I, Taxildaris K. 2009. Motor assessment of preschool aged children: A preliminary investigation of the validity of the Bruininks–Oseretsky Test of Motor Proficiency—Short form. Hum Mov Sci. 28(4):543-550. https://dx.doi.org/10.1016/j.humov.2009.03.002

Veselka L, Schermer JA, Just C, Hur YM, Rushton JP, Jeong HU, Vernon PA. 2012. Emotion and behavior: A general factor of personality from the EAS Temperament Survey and the Strengths and Difficulties Questionnaire. Twin Res Hum Genet. 15(5):668-671. https://dx.doi.org/10.1017/thg.2012.21

Wang HQ, Qu CY, Zhao SP. 2007. Standardization of the Griffith Mental Development Scales for children aged 0-7 years in the cities of Shanxi Province. Chin Mental Health J. 21(10):700-703.

Warren SL, Umylny P, Aron E, Simmens SJ. 2006. Toddler anxiety disorders: A pilot study. J Am Acad Child Adolesc Psychiatry. 45(7):859-866. https://dx.doi.org/10.1097/01.0000220852.94392.eb

Weinberg A, Klonsky ED. 2009. Measurement of emotion dysregulation in adolescents. Psychol Assess. 21(4):616-621. https://dx.doi.org/10.1037/a0016669

White RF, Diamond R, Krengel M, Lindem K. 1996. Validation of the NES2 in patients with neurologic disorders. Neurotoxicol Teratol. 18(4):441-448. https://dx.doi.org/10.1016/0892-0362(96)00021-9

White RF, James KE, Vasterling JJ, Letz R, Marans K, Delaney R, Krengel M, Rose F, Kraemer HC. 2003. Neuropsychological screening for cognitive impairment using computer-assisted tasks. Assessment. 10(1):86-101. https://dx.doi.org/10.1177/1073191102250185

Wiart L, Darrah J. 2001. Review of four tests of gross motor development. Dev Med Child Neurol. 43(4):279-285. https://dx.doi.org/10.1017/S0012162201000536

Wijedasa D. 2012. Developmental screening in context: adaptation and standardization of the Denver Developmental Screening Test-II (DDST-II) for Sri Lankan children. Child Care Health Dev. 38(6):889-899. https://dx.doi.org/10.1111/j.1365-2214.2011.01332.x

Williams J, Allison C, Scott F, Stott C, Bolton P, Baron-Cohen S, Brayne C. 2006. The Childhood Asperger Syndrome Test (CAST): Test-retest reliability. Autism. 10(4):415-427. https://dx.doi.org/10.1177/1362361306066612

Williams J, Scott F, Stott C, Allison C, Bolton P, Baron-Cohen S, Brayne C. 2005. The CAST (Childhood Asperger Syndrome Test): Test accuracy. Autism. 9(1):45-68. https://dx.doi.org/10.1177/1362361305049029

Wong BY, Roadhouse A. 1978. The Test of Language Development (TOLD): A validation study. Learn Disabil Q. 1(3):48-61. https://dx.doi.org/10.2307/1510937

Wong HS, Santhakumaran S, Cowan FM, Modi N. 2016. Developmental assessments in preterm children: A meta-analysis. Pediatrics. 138(2):1-12. https://dx.doi.org/10.1542/peds.2016-0251

Yao S, Zhang C, Zhu X, Jing X, McWhinnie CM, Abela JRZ. 2009. Measuring adolescent psychopathology: Psychometric properties of the self-report Strengths and Difficulties Questionnaire in a sample of Chinese adolescents. J Adolesc Health. 45(1):55-62.

Young S, González RA, Mutch L, Mallet-Lambert I, O'Rourke L, Hickey N, Asherson P, Gudjonsson GH. 2016. Diagnostic accuracy of a brief screening tool for attention deficit hyperactivity disorder in UK prison inmates. Psychol Med. 46(7):1449-1458. https://dx.doi.org/10.1017/S0033291716000039

Yu YT, Hsieh WS, Hsu CH, Chen LC, Lee WT, Chiu NC, Wu YC, Jeng SF. 2013. A psychometric study of the Bayley Scales of Infant and Toddler Development – 3rd Edition for term and preterm Taiwanese infants. Res Dev Disabil. 34(11):3875-3883.

Zarokanellou V, Kolaitis G, Vlassopoulos M, Papanikolaou K. 2017. Brief report: A pilot study of the validity and reliability of the Greek version of the Social Communication Questionnaire. Res Autism Spectr Disord. 38:1-5. https://dx.doi.org/10.1016/j.rasd.2017.03.001