# Appendix B Test Evaluation Tables

## B.1 Omnibus Tests

### B.1.1 General Intelligence/IQ

Table B-1 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess General Intelligence/IQ in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Kaufman Assessment Battery for Children (K-ABC); 1983 | A | A | A | D^3^ | A | A | NP^3^ | This IQ test is normed for children 2.5–12.5 years of age. It is used less often than Wechsler scales in both research and clinical settings, contributing to less knowledge about criterion validity. It has 16 subtests, 6 of which are nonverbal. Construct validity: The correlations between K-ABC and other measures of IQ are low, except for the Achievement outcome. Examiner qualifications: Data were not present in the sources consulted for the extraction table.^4^ Outcomes, domain-specific subscales, and subtests: The test comprises four domains—Achievement, Mental Processing, Sequential Processing, and Simultaneous Processing—and consists of 16 subtests. Achievement is based on six subtests (Expressive Vocabulary, Faces and Places, Arithmetic, Riddles, Reading/Decoding, Reading /Understanding); Sequential Processing is a composite of three subtests (Hand Movements, Number Recall, Triangles); and Simultaneous Processing is a composite of seven subtests (Magic Window, Face Recognition, Gestalt Closure, Word Order, Matrix Analogies, Spatial Memory, Photo Series). The Sequential Processing and Simultaneous Processing scales are combined to represent the Mental Processing Composite score. Composite standardized scores have a mean of 100 and standard deviation (SD) of 15. Each subtest standardized score has a mean of 10 and SD of 3. The subscales for this test that have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg are listed in the footnotes of evaluation tables for other domains, where applicable. Mental Processing appears in the Executive Function domain evaluation table. Subtests might be categorized in other domains but did not appear as outcomes in the literature queried for the in-progress EPA IRIS toxicological review of MeHg.
Kaufman Brief Intelligence Test (K-BIT); 1990 | A | A | A^3^ | A | A | A | NP^3^ | The K-BIT is a quick screening test for IQ (15–30 minutes) and is normed for ages 4–90 years. This test has been used for IQ screening in research. It has fewer subtests than its parallel Wechsler test (i.e., Wechsler Abbreviated Scale of Intelligence—WASI [1999] and WASI-II [2011]). Content validity: Sources consulted and summarized in the extraction table provided little information on theoretical or content bases for the test; however, item choice was presumed to have been driven by the tests from which the K-BIT was derived (Kaufman Adult Intelligence Test and the Kaufman Assessment Battery for Children). Examiner qualifications: Data were not present in the sources consulted for the extraction table. Outcomes, domain-specific subscales, and subtests: The K-BIT consists of two subtests—Vocabulary Performance and Matrices. Scores from these tests are summed to provide a Composite IQ score (standardized mean = 100, SD = 15). The Vocabulary Performance test provides a Verbal Intelligence score, and the Matrices test provides a Nonverbal Intelligence score, each with a standardized mean of 100 and SD of 15. The subtests for the K-BIT have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Vocabulary Performance subtest (Verbal domain) and Matrices subtest, also called Nonverbal Intelligence (Visuospatial domain).
McCarthy Scales of Children’s Abilities (MSCA); 1972^3^ | A | A | A | A | NP^3^ | A | A | This MSCA was developed for children 2.5–8.5 years old. The test and its normative sample are generally considered outdated. Year of publication: The year is sometimes listed as 1970. Criterion validity: Although this test predicts scores on other tests, its capacity to predict developmental outcomes was not described in the sources consulted and summarized in the extraction table. Outcomes, domain-specific subscales, and subtests: This test uses 18 short subtests to produce a General Cognitive Index, which would be considered the IQ outcome (standardized mean = 100, SD = 16). The 18 subtests can be categorized into domains producing several subscales, each of which has a standardized score with a mean of 50 and SD of 10. The subscales for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Verbal Index (Verbal domain), Perceptual Index (Visuospatial domain), Quantitative Index (Academic Achievement domain), Memory Index (Learning and Memory domain), and Motor Index (Motor Function domain). An Executive Function Index is also listed among these subscales in the in-progress EPA IRIS toxicological review of MeHg but was not reported in the test manual.
Raven’s Coloured Progressive Matrices (Raven’s CPM); 1965 | A | A | NP^3^ | NP^3^ | A | A | A | Unlike other tests listed in this evaluation table, Raven’s CPM is not a classic omnibus IQ test as defined in this document under domains. It is an older test developed in the United Kingdom. Although it directly measures executive function, it has often been used as a brief method to evaluate general intelligence. The test produces an “IQ”-like outcome (although the norms do not apply to most populations) and, given its availability for decades, has been used by neurotoxicologists and other researchers. It was developed for children 5–11 years old but has also been used with adult populations. Content validity: Data were not present in the sources consulted for the extraction table. Construct validity: Data were not present in the sources consulted for the extraction table. Outcomes, subscale, and subtest scores: IQ outcomes are classified using five gradations from superior (>95th percentile) to defective (<5th percentile).
Raven’s Standard Progressive Matrices (Raven’s SPM); 1977 | A | A | A | A | A | A | A | Unlike other tests listed in this evaluation table, Raven’s SPM is not a classic omnibus IQ test as defined in this document under domains. It is an older test developed in the United Kingdom. Although it directly measures executive function, is has often been used as a brief method to evaluate general intelligence. The test produces an IQ-like outcome (although the norms do not apply to most populations) and, given its availability for decades, has been used by neurotoxicologists and other researchers. It is often used in mercury studies to evaluate parent intelligence as a control measure, not outcomes in children. It was developed for children 6–13.5 years old but has been used with adult populations. Outcomes, subscale, and subtests scores: Percentile scores (5th, 10th, 25th, 50th, 75th, 90th, and 95th) are determined based on total raw score for all items.
Stanford-Binet Intelligence Scale: Fourth Edition (S-B 4); 1986 | A | A | A | A | A | A | A | Like the Wechsler scales, the Stanford-Binet scales have been used extensively both to assess general intelligence and to evaluate children with learning problems in school. The S-B 4 can be useful for individuals with very high or very low IQ as it is less subject to floor and ceiling effects compared with the Wechsler scales. The test can also be useful in longitudinal studies because many subtests can be given across the full age range, which is 2–90 years. Outcomes, subscale, and subtest scores: The S-B 4 provides a Full-Scale IQ score (standardized mean = 100, SD = 16). In addition, there are Verbal IQ and Nonverbal IQ scores and five factor indices (Fluid Reasoning, Knowledge, Quantitative Reasoning, Visual-Spatial Processing, and Working Memory), all with standardized means of 100 and SDs of 16. Subtest scores are standardized to a mean of 50 and SD of 8. The subtests for the S-B 4 have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include Total Copying (Visuospatial domain) and Copying Test Recall and Bead Memory (Learning and Memory domain).
Stanford-Binet Intelligence Scale: Fifth Edition (S-B 5); 2003 | A | A | A | A | A^3^ | A | A | The S-B 5 is a newer version of the S-B 4 and has similar advantages. It should be noted that some of the S-B 4 subtests are not included in the S-B 5, so the S-B 5 cannot be used as an updated version for these subtests. Criterion validity: This test has predictive validity for levels of intelligence and other outcomes similar to the S-B 4. Outcomes, subscale, and subtest scores: The S-B 5 provides Full-Scale, Verbal, and Performance IQs, all with a standardized mean of 100 and SD of 15. In addition, five factor indices (Fluid Reasoning, Knowledge, Quantitative Processing, Visual-Spatial Processing, and Working Memory) are standardized to scores with a mean of 100 and SD of 15. Subtest scaled scores have a mean of 10 and SD of 3. The subtests for the S-B 5 have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Knowledge Index (Verbal domain), Visuospatial Processing Index (Visuospatial domain), Quantitative Processing Index (Academic Achievement domain), and the Working Memory Index (Executive Function domain).
Wechsler Intelligence Scale for Children (WISC); 1949 | A | A | A^3^ | A | A^3^ | A | NP^3^ | Information on the WISC from the peer-reviewed literature was limited. Some of the conclusions below are based on experience using the test.^4^ Content validity: The source consulted for the extraction table suggests there is no available information on content validity; however, personal experience^4^ indicates adequate content validity. This version of the WISC is the basis for all future versions of the WISC. Criterion validity: The source consulted for the extraction table suggests criterion validity is inadequate; however, personal experience^4^ indicates adequate criterion validity in pediatric populations. Examiner qualifications: Data were not present in the sources consulted for the extraction table.
Wechsler Intelligence Scale for Children-Revised (WISC-R); 1974 | A | A | A | A | A^3^ | A | A | This widely used standard test of general abilities is a revision of the original Wechsler Intelligence Scale for Children (WISC). The WISC-R includes 12 subtests, and 10 of 12 (5 verbal, 5 nonverbal) are used to determine IQ. Because of its widespread use, The WISC-R has been applied to the domain-specific functioning associated with neuropsychological assessment. It is designed for children aged 6–16 years. For all editions of the WISC, there is some overlap with the WAIS (adult version of Wechsler test) at age 16. In general, for persons of average or above-average intelligence, the WAIS tests are more appropriate for 16-year-olds. This is not true for children of less-than-average intelligence. Criterion validity: The WISC-R correlates with many other established measures of intelligence and predicts learning disabilities and other outcomes in children. Outcomes, subscale, and subtest scores: Outcome measures include Full-Scale, Verbal, and Performance IQ scores, all with a standardized mean of 100 and SD of 15. The 12 subtest scaled scores have a mean of 10 and SD of 3. The subtests for the WISC-R have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Verbal IQ outcome and the Similarities subtest (Verbal domain) and the Performance IQ outcome and Block Designs subtest (Visuospatial domain).
Wechsler Intelligence Scale for Children-III (WISC-III); 1991 | A | A | A | A | A | A | A | This revision of the WISC-R is similar to its predecessor but adds a new subtest, Symbol Search. The WISC-III further advances the idea of domain-specific assessment by including four index scores—Verbal Comprehension, Perceptual Organization, Freedom from Distractibility, and Processing Speed. Outcomes, subscale, and subtest scores: Outcome measures include Full-Scale, Verbal, and Performance IQ scores, all with a standardized mean of 100 and SD of 15. The four index scores also have a standardized mean of 100 and SD of 15, and the 13 subtest scaled scores have a mean of 10 and SD of 3. The index scores and subtests for the WISC-III have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Verbal IQ outcome, Information subtest, and Vocabulary subtest (Verbal domain); the Performance IQ outcome and Block Designs subtest (Visuospatial domain); and the Coding subtest (Motor Function domain).
Wechsler Intelligence Scale for Children-IV (WISC-IV); 2003 | A | A | A^3^ | A | A^3^ | A | A | The WISC-IV removed three subtests and added five new subtests relative to the WISC-III for a total of 15 subtests. It includes four index scores, but one has changed from Freedom from Distractibility to Processing Speed. Content validity: This test has content validity similar to that of prior versions of the WISC. It is also based on psychometric theory, which has affected the index outcome revisions and subtest additions. Criterion validity: This test has criterion validity similar to that of prior versions of the WISC. Outcomes, subscale, and subtest scores: Outcome measures include Full-Scale, Verbal, and Performance IQ scores (standardized mean = 100, SD = 15). The index scores have a mean of 100 and SD of 15, and the 15 subtest scaled scores have a mean of 10 and SD of 3. The index scores for the WISC-IV have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Verbal Comprehension Index (Verbal domain), Processing Speed Index (Miscellaneous domain), and the Perceptual Reasoning Index (Visuospatial domain).
Wechsler Preschool and Primary Scale of Intelligence-Revised (WPPSI-R); 1989 | A | A | A | A | A | A | A | The WPPSI scales are designed for children aged 3 years to 7 years, 3 months. This test has some age overlap with the WISC scales at ages 6 years to 7 years, 3 months. In this age range, the WPPSI-R is considered too easy for some children or populations, making the WISC more appropriate. The test has 11 subtests that all contribute to the Full-Scale IQ, with 5 contributing to the Performance IQ and 6 contributing to the Verbal IQ. Outcomes, subscale, and subtest scores: Outcome measures include Full-Scale, Verbal, and Performance IQ scores (standardized mean = 100, SD = 15). Age-scaled scores (standardized mean = 10, SD = 3) are available for the subtests at 3-month age intervals. The index scores for the WPPSI-R have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include Verbal IQ (Verbal domain) and Performance IQ (Visuospatial domain).
Wechsler Adult Intelligence Scale-Revised (WAIS-R); 1981 | A | A | A | A | A^3^ | A | A | This test is a revision of the 1955 Wechsler Adult Intelligence Scale (WAIS), which was based on the Wechsler-Bellevue Intelligence Scale (W-B) and contains the same 11 subtests in revised form. It is standardized for persons aged 16 years to 74 years, 11 months. It has ceiling and floor effects, meaning that IQ scores above 135 or below 70 may not be as precise as high or low scores on other intelligence tests. Because it has been widely applied, a great deal is known about the relationship between performance on WAIS-R subtests and outcomes such as localized brain damage and neuropsychiatric disorders. Criterion validity: This test’s criterion validity derives at least in part from that of WAIS and W-B, which correlate highly with clinician ratings of individual intelligence, “empirical studies of several groups of known intellectual level” (manual, p. 49), and WAIS correlations with academic success (WAIS manual, p. 50). Outcomes, subscale, and subtest scores: Administration of the WAIS-R allows derivation of Full-Scale, Verbal, and Performance IQs (standardized mean = 100, SD = 15). In addition, each subtest can be scored according to age-appropriate norms with a standardized mean of 10 and SD of 3. The subtests for the WAIS-R have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Block Design subtest (Visuospatial domain).
Wechsler Adult Intelligence Scale-III (WAIS-III); 1997 | A | A | A | A | A | A | A | This revision of the WAIS-R is designed for ages 16–89 years. Because its norms start at age 16 years, it can be an appropriate test for older children of average or above-average intelligence and can be used in place of the WISC scales. There are 14 subtests included in the WAIS-III—11 revisions of WAIS-R subtests and 3 new subtests. This version of the Wechsler adult scales has a somewhat lower floor (45) and higher ceiling (155) than the WAIS-R, but still does not measure extremes of intelligence. Outcomes, subscale, and subtest scores: Administration of the WAIS-III allows derivation of Full-Scale, Verbal, and Performance IQs (standardized mean = 100, SD = 15) as in prior adult scales. In addition, there are four subscale outcomes (Verbal Comprehension Index, Perceptual Organization Index, Working Memory Index, and Processing Speed Index), with standardized means of 100 and SDs of 15. Subtests have age norms that produce age-scaled scores with standardized means of 10 and SDs of 3. The index scores and subtests for the WAIS-III have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Vocabulary subtest, Similarities subtest, and Comprehension subtest (Verbal domain); the Block Design subtest, Matrix Reasoning subtest, Picture Completion subtest, Object Assembly subtest, and Picture Arrangement subtest (Visuospatial domain); Digit Symbol/Coding subtest (Motor Function domain); and the Processing Speed Index (Miscellaneous domain).

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ Adequacy and deficiency are determined by the professional experience and knowledge of the co-author Dr. Roberta F. White.

* Subtests or scales within tests that belong to a different domain may be applicable to general intelligence/IQ. This includes the Bayley Scales of Infant Development-II: Mental Development Index (Developmental domain).

Table B-2 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess General Intelligence/IQ in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Kaufman Assessment Battery for Children (K-ABC); 1983 | A | NA | A | NA | A | NA | None.
Kaufman Brief Intelligence Test (K-BIT); 1990 | NP^3^ | NP^3^ | A | A | NP^3^ | NP^3^ | Subject age (child & adult): The standardization sample was divided into four wide age bands (4–6, 7–19, 20–44, 45–92), but the sources cited in the extraction table state that it is not clear if these were used for the age-standardized scores or if they were based on more precise data. Since the sample size was 2,022 and ages of the sample were “proportional,” it is not clear how many people were in each age band, but there would be many age bands needed for the children and adults. Ultimately, it is unclear from the sources consulted for the extraction table if age bands were further divided for normative scores. Sample size (child & adult): 2,022 participants in total comprised the sample. It is not clear if age bands were sufficiently well populated for children. Assuming 10-year age bands, there may have been a large enough sample of adults.
McCarthy Scales of Children’s Abilities (MSCA); 1972^3^ | A | NA | A | NA | A | NA | Year of publication: The year is sometimes listed as 1970.
Raven’s Coloured Progressive Matrices (Raven’s CPM); 1965 | A | D^3^ | D^3^ | D^3^ | D^3^ | D^3^ | Subject age (adult): Adult norms exist for persons 60–85 years and do not represent younger adults. Population representation (child & adult): Child and adult norms are based on populations from a single area in the United Kingdom. Sample size (child & adult): Child norms appear to be based on 627 children. It is not clear what the age ranges are for the adult standardization sample. Adult norms are only based on 271 individuals from the United Kingdom.
Raven’s Standard Progressive Matrices (Raven’s SPM); 1977 | A | A | D^3^ | D^3^ | A | A | Population representation (child & adult): Child samples are from limited areas of the United Kingdom. Adult normative samples include military personnel and civilians (undefined).
Stanford-Binet Intelligence Scale: Fourth Edition (S-B 4); 1986 | A | A | A | A | A | A | None.
Stanford-Binet Intelligence Scale: Fifth Edition (S-B 5); 2003 | A | A | A | A | A | A | None.
Wechsler Intelligence Scale for Children (WISC); 1949 | A | NA | A | NA | A | NA | None.
Wechsler Intelligence Scale for Children-Revised (WISC-R); 1974 | A | NA | A | NA | A | NA | None.
Wechsler Intelligence Scale for Children-III (WISC-III); 1991 | A | NA | A | NA | A | NA | None.
Wechsler Intelligence Scale for Children-IV (WISC-IV); 2003 | A | NA | A | NA | A | NA | None.
Wechsler Preschool and Primary Scale of Intelligence-Revised (WPPSI-R); 1989 | A | NA | A | NA | A | NA | None.
Wechsler Adult Intelligence Scale-Revised (WAIS-R); 1981 | A | A | A | A | A | A | None.
Wechsler Adult Intelligence Scale-III (WAIS-III); 1997 | A | A | A | A | A | A | None.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ The link to the extraction table is provided in Appendix C.

### B.1.2 Academic Achievement

Table B-3 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Academic Achievement in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
KeyMath Diagnostic Arithmetic Test; 1976^3^ | A | NP^3^ | A | A | A^3^ | A^3^ | NP^3^ | Year of publication: The KeyMath, American edition was first published by American Guidance Service in 1976. The Canadian edition was published by Psycan in 1979, and a supplemental norms table was published by American Guidance Service in 1983.This test is appropriate for children “preschool” age through grade 6. Test-retest reliability: Data were not present in the sources consulted for the extraction table.^4^ Criterion validity: No specific information on criterion validity is reported in the sources consulted and summarized in the extraction table; however, the information on predictive validity indicates that criterion validity is adequate. Instructions/manual: Data in the extraction table come from sources other than the manual, and ratings reflect statements from those sources. There are manuals available that could be consulted. Examiner qualifications: Data were not present in the sources consulted for the extraction table.
KeyMath Diagnostic Arithmetic Test-Revised (KeyMath R); 1991 | A | NP^3^ | A | A | A^3^ | A^3^ | NP^3^ | This test is appropriate for children ages 5 years, 6 months through 15 years, 5 months (or grades K through 8). Test-retest reliability: Data were not present in the sources consulted for the extraction table. Criterion validity: No specific information on criterion validity is reported in the sources consulted and summarized in the extraction table; however, the information on predictive validity indicates that criterion validity is adequate. Instructions/manual: Data in the extraction table come from sources other than the manual, and ratings reflect statements from those sources. There are other manuals that could be consulted. Examiner qualifications: Data were not present in the sources consulted for the extraction table.
Wechsler Individual Achievement Test (WIAT); 1992 | A | A | A | A | D^3^ | A | A | The WIAT is designed for use on children grades K through 12. Criterion validity: Correlations between WIAT test performance and school grades are poor.
Woodcock-Johnson III Test of Achievement (WJ III ACH); 2001 | A | A | A | A | A^3^ | A | A | Administration of individual subtests within the WJ III varies depending upon age. Norms are available by month from age 24 months to 19 years and by year from ages 20 to 90+ years. Criterion validity: No specific information on criterion validity is reported in the sources consulted and summarized in the extraction table; however, the information on discriminant validity indicates that criterion validity is adequate. Outcomes, subscales, and subtest scores: Outcomes are scored with a standardized mean of 100 and standard deviation (SD) of 15. The index scores and subtests for the WJ III that have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg are Antonyms, Concept Formation, Decision Speed, Memory for Words, Numbers Reversed, Spatial Relations, Synonyms, Verbal Analogies, Visual Matching, Applied Problems, Calculation, Letter-Word, Math Fluency, and Passage Comprehension (Academic Achievement domain).

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ The link to the extraction table is provided in Appendix C.

* Subtests or scales within tests that belong to a different domain may be applicable to academic achievement. These include the Kaufman Assessment Battery for Children (KAB-C): Achievement Index (IQ domain); McCarthy Scales of Children’s Abilities (MSCA): Quantitative Index (IQ domain); and Stanford-Binet, 5th Edition: Quantitative Processing Index (IQ domain).

Table B-4 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Academic Achievement in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
KeyMath Diagnostic Arithmetic Test; 1976^3^ | NP^3^ | NA | A | NA | A | NA | Year of publication: The KeyMath, American edition, was first published by American Guidance Service in 1976. The Canadian edition was published by Psycan in 1979, and a supplemental norms table was published by American Guidance Service in 1983. Subject age (child): Data were not present in the sources consulted for the extraction table.^4^
KeyMath Diagnostic Arithmetic Test-Revised (KeyMath R); 1991 | A^3^ | NA | A | NA | A | NA | Subject age (child): Grade-level normative bands are used instead of age-based normative bands. Although there may be some age misclassification (e.g., a 16-year-old middle school student), this is thought to occur infrequently.
Wechsler Individual Achievement Test (WIAT); 1992 | A | NA | A | NA | A | NA | None.
Woodcock-Johnson III Test of Achievement (WJ III ACH); 2001 | A | NA | A | NA | A | NA | None.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ The link to the extraction table is provided in Appendix C.

### B.1.3 Developmental

Table B-5 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess the Developmental Domain in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Bayley Scales of Infant Development (BSID-1);1969^3^ | A | A | A^3^ | A | A^3^ | A^3^ | A^3^ | This test assesses aspects of cognition labeled “mental” in the test manual. It assesses motor and social behaviors in very young children—ages 2 months to 2 years of age. Content validity: Evaluation is based on correlations with BSID-2. Criterion validity: Criterion validity depends on age. When the test is given at very young ages, correlations with both later-in-life BSID scores and later IQs can be very low. Instructions/manual: Data in the extraction table^4^ come from text (Spreen and Strauss), and ratings reflect statements from that text. There is a manual with explicit instructions.^5^ Examiner qualifications: These are not well defined. This test is difficult to give without training from an experienced administrator, and the instructions allow for a great deal of leeway, which can ultimately affect scores. Outcomes, subscale, and subtest scores: The index scores and subtests for the BSID-1 have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are the Mental Development Index (MDI) (IQ domain) and Psychomotor Index (Visuospatial domain), which represent the overall outcome scores for the test with standardized means of 100 and standard deviations (SDs) of 15.
Bayley Scales of Infant Development, Second edition (BSID-II); 1993^3^ | A | A | A | A | A | A | A^3^ | The age range for the test is 1 month to 42 months. Year of publication: The publication year of 1993 is from the Psychological Corporation by author Nancy Bayley. The original BSID was copyrighted in 1969. This test is a revision of the BSID-I. Examiner qualifications: Examiners require extensive training. Outcomes, subscale, and subtest scores: The Mental and Motor Index scores have a standardized mean of 100 and SD of 15. The index scores for this test have been identified in the epidemiologic literature for in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Mental Development Index (IQ domain) and the Motor Index (Motor Function domain).
Bayley Scales of Infant Development-III (BSID-3); 2006 | A | A | A | A | A | A | A^3^ | The BSID-III represents the second revision of the test and is appropriate for children aged 1 month to 42 months. Examiner qualifications: Examiners require extensive training. Outcomes, subscale, and subtest scores: The test includes three domains—Cognitive, Language, and Motor—which have subscale scores. Domains and subtests can be scored with age-adjusted normative outcomes of several types.
Brazelton Newborn Assessment Scale (NBAS); 1973 | D^3^ | D^3^ | A | D^3^ | A^3^ | A | A^3^ | This test was developed for infants 1 day to 1 month, although some items can be administered through 10 weeks old. It is used clinically and may be more valuable in clinical situations in which testing is done by an experienced clinician.^5^ Internal consistency: Data suggest inter-item consistency ranges from 0.15 to 0.52. Low correlations may in part reflect heterogeneity of test items. (In addition, the review of quantitative outcomes suggests that data analysis is challenging due to the correlations of the behavioral items on the inventory and nature of the data.) Test-retest reliability: This test measures moment-to-moment state behaviors in children and appears to have face validity, but this makes it unreliable in some ways.^5^ Construct validity: This test does not correlate well with other tests. Criterion validity: The test correctly predicted mild and moderate disability among preterm infants. Examiner qualifications: Research assistants with experience in the care and assessment of young infants can reliably administer these scales with extensive training from a certified examiner. Outcomes, subscale, and subtest scores: This test produces 6 main cluster scores ranging from 1 to 9, 7 supplementary scores ranging from 1 to 9, and 18 reflex/motor scores ranging from 0 to 3. The index scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are Autonomic Stability, Habituation, Motor, Orientation, Range of State, Reflexes, and Regulation of State (Developmental domain).
Denver Development Screening Test (DDST); 1967 | NP^3^ | A | A^3^ | A^3^ | D^3^ | A^3^ | A^3^ | DDST is designed for children from birth to 6 years. Internal consistency: Data were not present in the sources consulted for the extraction table. Content validity: This test has inherent content validity as a measure of developmental milestones. Construct and criterion validity: Data in the extraction table show good correlations with other developmental tests in 236 pediatric patients. A study on validity in 2,569 children is described in the extraction table, but the outcomes are not clearly described. Low sensitivity and under-referral rate indicate that the instrument is not consistently predictive of developmental deficits, which supports a criterion validity rating of deficient. Instructions/manual: Data in the extraction table come from validation papers, and ratings reflect statements from these papers. There is a test manual. Examiner qualifications: Examiner qualifications are discussed but are not specific. Outcomes, subscale, and subtest scores: The four scored developmental areas include gross motor, fine motor, language, and social and personal skills. They are scored as normal, questionable, or abnormal. The scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. They include Communication (language area, Verbal domain); Fine Motor Skills and Gross Motor Skills (Motor Function domain); and Social Skills (social/emotional area, Social/Emotional domain).
Denver Development Screening Test-II (DDST II); 1992 | A | A | A^3^ | A^3^ | A^3^ | A^3^ | A^3^ | This test is designed for neonates through 6 years of age. Content validity: The content validity rating is based on DDST. Construct and criterion validity: Validity and correlations with other developmental tests and with diagnostic outcomes are adequate in summaries provided in the extraction table for children at older ages, but not for children 2 years of age or younger. These studies are based on highly specific populations. Instructions/manual: Data in the extraction table come from validation papers, and ratings reflect statements from these papers. There is a test manual. Examiner qualifications: Examiner qualifications are discussed but are not specific.
Fagan Test of Infant Intelligence; 1985 | D^3^ | D^3^ | A^3^ | A^3^ | D^3^ | A^3^ | A^3^ | This test is designed for infants ages 27–52 weeks and is corrected for prematurity. Reliability: According to sources consulted for the extraction table, internal consistency and test-retest reliability were low. This is probably due to the variety of test items and ages of infants and may not be a surmountable issue for this type of test. Validity (in general): Studies reported in extraction table show adequate values but are based on small sample sizes. Criterion validity: Per the data in the extraction table, the test predicts normal development adequately but is deficient for abnormal development. Instructions/manual: There are explicit instructions. Examiner qualifications: Examiners are trained using a training manual and videotape. Outcomes, subtest, and subscale scores: The scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. This includes the Visual Attention outcome (Attention domain) and Visual Recognition Memory outcome (Learning and Memory domain), which have associated “novelty scores” determined by the computer when the baby responds to stimuli.
Gesell Developmental Schedules; 1925^3^ | NP^3^ | NP^3^ | A^3^ | A | NP^3^ | A | NP^3^ | This test was developed for children from neonate to 56 weeks. Year of publication: The Gesell Developmental Schedules appear to have been republished or revised in 1940 and 1949. Internal consistency: Data were not present in the sources consulted for the extraction table. Test-retest reliability: This is not discussed in the papers consulted for the extraction table. The data summarized in the extraction table indicate that test performance at 3-month intervals starting at 3 months was not well correlated with that at later ages (which is more a measure of validity), but the sources consulted do not provide data on test-retest reliability at the same age. Content validity: At the time this test was developed, it had content validity; however, this test was based on theory from an earlier time, and what is known about neurodevelopment has evolved since then. Criterion validity: Data were not present in the sources consulted for the extraction table. Examiner qualifications: Data were not present in the sources consulted for the extraction table. It is known that examiners require extensive training.
Griffith Mental Development Scales (GMDS); 1970 | NP^3^ | A | A | A | NP^3^ | NP^3^ | A^3^ | The age range for this test is birth to 1 year, 11 months. Since it was published and normed around 1970, the timeframe in which it was applied to research must be considered. Internal consistency: Data were not present in the sources consulted for the extraction table. Criterion validity: Data were not present in the sources consulted for the extraction table. Instructions/manual: Data were not present in the sources consulted for the extraction table. Instructions may be available in papers that were not consulted for the extraction table.^5^ Examiner qualifications: Information on examiner qualifications was not directly available from sources consulted for the extraction table; however, “Griffiths certified examiners” are mentioned, indicating that expert examiners trained other examiners. Outcomes, domain-specific subscales, and subtests: Scores for this test as a whole (General Quotient) and for the five subscales are based on standardized mean of 100 and SD of 15. The subscales for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include Hand-eye Coordination Index and Locomotion Index (Motor Function domain), Hearing and Speech Index (Verbal domain), Hand-eye Performance Index (Visuospatial domain), and Personal/Social Skills subscale (Social-Emotional domain).
Kyoto Scale of Psychological Development (KSPD; K-test); 2002 | A | NP^3^ | A^3^ | A^3^ | A^3^ | A^3^ | A | It appears that this test was developed for Japanese children ages 0–5 years. Test-retest reliability: Data were not present in the sources consulted for the extraction table. Validity (in general): Studies in Japan show that the test correlates with another Japanese developmental test and predicts developmental abnormalities of various types. Criterion validity: The sources consulted for the extraction table describe a study of children with known developmental disorders. As a group, they performed below average on the developmental quotient (DQ) outcome. Instructions/manual: The sources consulted for the extraction table cite administration manuals in Japan.
Neonatal Intensive Care Unit Network Neurobehavioral Scale (NNNS); 2004 | A | NP^3^ | A | A | A | A | A^3^ | Gestational ages 30–48 weeks is the target age range for this test. Test-retest reliability: Data were not present in the sources consulted for the extraction table. Examiner qualifications: Research assistants with experience in the care and assessment of young infants can reliably administer these scales with extensive training from a certified examiner.
Prechtl General Movement Assessment (GMA); 1977^3^ | NP^3^ | A^3^ | A^3^ | A | A^3^ | A^3^ | NP^3^ | Age of administration is 0–4 months. Year of publication: The year is sometimes listed as 2004, specifically to general movements (GMs) or the General Movements Assessment (GMsA). Internal consistency: Data were not present in the sources consulted for the extraction table. Test-retest reliability: The extraction table mentions an intra-rater study that is small but indicates adequacy. Content validity: Content validity is based on theory. Criterion validity: Predictive validity has been indicated as adequate in a few small studies. This test seems to predict cerebral palsy well. Instructions/manual: Data in the extraction table come from validation papers, and ratings reflect statements from these papers. A formal assessment system appears to exist and could be consulted. Examiner qualifications: The sources consulted for the extraction table report that videos are used for scoring, but do not indicate who is qualified to rate them.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ The link to the extraction table is provided in Appendix C.

^5^ Adequacy and deficiency are determined by the professional experience and knowledge of the co-author Dr. Roberta F. White.

Table B-6 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess the Developmental Domain in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Bayley Scales of Infant Development (BSID-1); 1969^3^ | NP^3^ | NA | A^3^ | NA | A | NA | Year of publication: The year is sometimes listed as 1969. The manual may be available at Psychological Corporation. Subject age: The sources consulted for the extraction table do not provide information on the age bands in the normative sample. Population representation: The standardization sample is noted in the extraction table as being reasonably representative of the U.S. population, but is otherwise not described.
Bayley Scales of Infant Development, Second edition (BSID-II); 1993^3^ | A | NA | A | NA | A | NA | Year of publication: The year of 1993 is from the Psychological Corporation by author Nancy Bayley. The original BSID was copyrighted in 1969.
Bayley Scales of Infant Development-III (BSID-3); 2006 | A | NA | A | NA | A | NA | None.
Brazelton Newborn Assessment Scale (NBAS); 1973 | NP^3^ | NA | NP^3^ | NA | NP^3^ | NA | There was inadequate information on test norms in the sources consulted for the extraction table.
Denver Development Screening Test (DDST); 1967 | NP^3^ | NA | D^3^ | NA | A | NA | Subject age (child): Age bands are not described in validation studies per the extraction table but may be in the manual. Population representation (child): The standardization sample is limited to Denver children. The representativeness was not described in sources consulted for the extraction table.
Denver Development Screening Test-II (DDST II); 1992 | NP^3^ | NA | D^3^ | NA | A | NA | Subject age (child): Age bands were not described in the sources consulted for the extraction table but may be available in the manual. Population representation (child): Several specific population normative studies are described in the extraction table. The initial sample was 2,096 children “from all over Colorado.”
Fagan Test of Infant Intelligence; 1985 | NP^3^ | NA | D^3^ | NA | D^3^ | NA | Subject age (child): The sources consulted for the extraction table did not provide information on age bands used in the normative sample. Population representation (child): The normative sample was not designed to represent a population. Sample size (child): The normative sample size was relatively small (<250 children).
Gesell Developmental Schedules; 1925^3^ | A^3^ | NA | D^3^ | NA | A^3^ | NA | Year of publication: The Gesell Developmental Schedules appears to have been republished or revised in 1940 and 1949. Subject age (child): Age bands of 4-week intervals from newborn to 56 weeks were used. Population representation (child): The standardization sample consisted of 107 middle class infants from North America. Sample size (child): Although the sample size only consisted of 107 infants, they were repeatedly tested, which yielded repeated measures of the same children.
Griffith Mental Development Scales (GMDS); 1970 | NP^3^ | NA | NP^3^ | NA | A | NA | Subject age (child): Infants and children ages 6, 12, and 24 months were included in the standardization sample. There is no information in the sources consulted and summarized in the extraction table on the age bands used to calculate the outcomes. Population representation (child): Information on the representativeness of the sample from the United Kingdom was not available from sources consulted and summarized in the extraction table.
Kyoto Scale of Psychological Development (KSPD; K-test); 2002 | NP^3^ | NA | NP^3^ | NA | A | NA | Subject age (child): Normative studies are not detailed in the sources consulted for the extraction table. Population representation (child): Normative study populations are not detailed in the sources consulted for the extraction table.
Neonatal Intensive Care Unit Network Neurobehavioral Scale (NNNS); 2004 | NP^3^ | NA | D^3^ | NA | A | NA | Subject age (child): No age band data are present in the sources consulted for the extraction table. Population representation (child): A normative study of children in Boston is described in the extraction table, which would not be considered representative.
Prechtl General Movement Assessment (GMA); 1977 | NP^3^ | NA | D^3^ | NA | A^3^ | NA | Year of publication: The year is sometimes listed as 2004, specifically to general movements (GMs) or General Movements Assessment (GMsA). Subject age, population representation, sample size (child): The data in the extraction table do not suggest that true norms or normative samples exist. A sample of 233 infants for whom 783 video recordings were available is described; all children were at high risk for neurodevelopmental disorders.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.1.4 Neuropsychological Assessment Batteries

Table B-7 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Neuropsychological Assessment Batteries in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Developmental Neuropsychological Assessment (NEPSY); 1998 | NP^3^ | A | A | A | A | A | A^3^ | This test is designed for children 3–12 years of age. Internal consistency: Data were not present in the sources consulted for the extraction table. To be meaningful, this would have to be calculated separately for each subtest or domain, as the subtests and subscales measure different constructs associated with brain function and brain damage. Examiner Qualifications: This test is a difficult instrument to master when all or many subtests are administered (some studies select only one or two subtests, as there is not an overall omnibus score result). The use of multiple NEPSY subtests requires extensive training and supervision by a developmental neuropsychologist. Outcomes, subscale, and subtest scores: Composite domain scores (standardized mean = 100, standard deviation [SD] = 15) are calculated from the standard scores associated with subtests (mean = 10, SD = 3). The applicable subtests depend upon the age of the child. The domain composite scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. These include the Attention subscale and the Executive Function subscale.
Neurobehavioral Evaluation System (NES); 1985 | A | A | A | A^3^ | A^3^ | A^3^ | A | The NES is designed for adults; some subtests have been adapted for children. This is a computer-administered test designed for research; outcomes are the scores on tasks which, in research, are adjusted for relevant variables. Construct validity: The NES is correlated with analogous noncomputerized tests. Criterion validity: The Adequate rating is based on personal knowledge and research.^4^ Specific subtests have been found to be associated with toxicant exposure and certain neurological disorders. Instructions/manual: The NES is a computer-administered test with an examiner present.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ Adequacy and deficiency are determined by the professional experience and knowledge of the co-author Dr. Roberta F. White.

Table B-8 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess the Neuropsychological Assessment Batteries Domain in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Developmental Neuropsychological Assessment (NEPSY); 1998 | A | NA | A | NA | A | NA | None.
Neurobehavioral Evaluation System (NES); 1985 | NP^3^ | NP^3^ | NP^3^ | NP^3^ | NP^3^ | NP^3^ | Norms (child & adult): The NES does not utilize normative data; outcomes are raw scores, adjusted for factors including age, gender, and education.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

## B.2 Clinical Assessment Instruments

### B.2.1 Clinical Conditions

Table B-9 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Clinical Conditions in Developmental Neurotoxicity studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Autism Spectrum Quotient (AQ); 2001 | A | A | A | A | A | A | A^3^ | This test has a child version that starts at age 4, an “adolescent” version for ages 9.8–15.4 years, and an adult version for ages 16 and above. Examiner qualifications: This is a self-administered questionnaire.
Barkley Adult ADHD Rating Scale-IV; 2011 | A | A | A^3^ | A | A^3^ | A | A^3^ | The age range for the test is 15–89 years. Content validity: The rating is based on Diagnostic and Statistical Manual (DSM) criteria for developmental disorders. Criterion validity: Convergent and divergent validities are demonstrated. Examiner qualifications: This is a self-reported measure.
Childhood Asperger’s Syndrome Test (CAST); 2002 | NP^3^ | A | A^3^ | A^3^ | A | A | A^3^ | The age range for this test is 4–11 years. Internal consistency: Data were not present in the sources consulted for the extraction table. Content validity: This test uses items that reflect Asperger’s symptoms. Construct validity: The results from the criterion validity studies suggest construct validity. Examiner qualifications: This is a parent-completed questionnaire.
Childhood Autism Rating Scale (CARS); 1980 | A | NP^3^ | A | A^3^ | A | A | A^3^ | This test is designed for children up to 10 years of age. Test-retest reliability: Data were not present in the sources consulted for the extraction table. Construct validity: The results from the criterion validity studies suggest construct validity. Examiner qualifications: Sources consulted for the extraction table indicate that examiners have been trained by the test authors and that clinical psychologists have carried out the test in at least one study.
Conners’ Parent Rating Scale-Revised (CPRS-R); 1997^3^ | A | A | A | A | A | A^3^ | A | The parent and teacher scales are essentially the same test and manual. Parents rate children 3–17 years of age. Year of publication: This test was also published in 2000 and 2001. Instructions/manual: It is unclear how explicit the manual is regarding instructions to raters. Outcomes, subscales, and subtest scores: The index scores and subtests for the CPRS-R have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are ADHD Index (T-scores based on normative sample) (Clinical Conditions domain), and Behavioral Index, Externalizing Problems, Hyperactivity Index, and Oppositional Index (Social-Emotional domain).
Conners’ Teacher Rating Scale-Revised (CTRS-R); 1997^3^ | A | A | A | A | A | A^3^ | A | The parent and teacher scales are essentially the same test and manual. Teachers rate children 3–17 years of age. Year of publication: This test was also published in 2000 and 2001. Instructions/manual: It is unclear how explicit the manual is regarding instructions to raters.
Spence Children’s Anxiety Scale (SCAS); 1994 | A | A | A | A | NP^3^ | A | A^3^ | The age range for this test is 8–12 years. Criterion validity: Data were not present in the sources consulted for the extraction table. Examiner qualifications: This is a self-report questionnaire completed by children.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

* Subtests or scales within tests that belong to a different domain may be applicable to clinical conditions. This includes the Conners’ Parent Rating Scale-R: ADHD Index (Attention domain).

Table B-10 Adequacy or Deficiency of Factors Affecting the Normative Data Standards of Psychometric Tests Used to Assess Clinical Conditions in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Autism Spectrum Quotient (AQ); 2001 | NP^3^ | D^3^ | NP^3^ | A^3^ | NP^3^ | D^3^ | Subject age, population representation, and sample size (child): Data are not present in the sources consulted for the extraction table. Subject age (adult): Adult samples are obtained from a narrow age range of young adults with no age bands. Population representation (adult): The normative population includes autism cases plus randomly selected controls from East Anglia. Sample size (adult): The adult norms are based on a sample of 58 adults with autism spectrum disorders and 174 controls.
Barkley Adult ADHD Rating Scale-IV; 2011 | NA | A^3^ | NA | A^3^ | NA | A | Subject age (adult): Age bands are not discussed in the extraction table. The test is normed for adults 18–89 years. Population representation (adult): Normative data are drawn from a U.S. census-matched sample. The test is representative for the United States.
Childhood Asperger’s Syndrome Test (CAST); 2002 | D^3^ | NA | D^3^ | NA | D^3^ | NA | Subject age, population representation, and sample size (child): The sources consulted for the extraction table suggest normative studies have not been conducted. The instrument was developed in the United Kingdom.
Childhood Autism Rating Scale (CARS); 1980 | D^3^ | NA | D^3^ | NA | A | NA | Subject age (child): Over half of the normative age sample was less than 6 years of age, and only 11% were aged 10 years or older. Thus, the number of children in some of the age bins appears to be insufficient. Population representation (child): Normative data use a convenience sample with very specific characteristics.
Conners’ Parent Rating Scale-Revised (CPRS-R); 1997 | A | NA | A | NA | A | NA | None.
Conners’ Teacher Rating Scale-Revised (CTRS-R); 1997 | A | NA | A | NA | A | NA | None.
Spence Children’s Anxiety Scale (SCAS); 1994 | NP^3^ | NA | D^3^ | NA | A^3^ | NA | Subject age (child): Age bands are not reported in the sources consulted for the extraction table. Population representation (child): Normative data use a convenience sample in Brisbane. Sample size (child): Confirmatory factor analytic studies have been done on approximately 1,400 children.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.2.2 Mental Status

Table B-11 Adequacy of Factors Affecting the Reliability, Validity, and Administration Standards of Tests Used to Assess Mental Status in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Mini-Mental State Examination (MMSE); 1975 | NP^3^ | A | A^3^ | A^3^ | A | A | NP^3^ | The MMSE is typically administered to adults and not children. Internal consistency: Internal consistency may be limited due to heterogeneity of items measuring different constructs. Content validity: The adequate rating is based on personal knowledge; the test assesses common mental status domains.^4^ Construct validity: The adequate rating is based on correlation with other similar tests. Examiner qualifications: This test can be given by a wide variety of practitioners.^4^

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ Adequacy and deficiency are determined by the professional experience and knowledge of the co-author Dr. Roberta F. White.

Table B-12 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Mental Status in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Mini-Mental State Examination (MMSE); 1975 | NA | NP^3^ | NA | NP^3^ | NA | NP^3^ | Norms (adult): No information on normative data was provided in the sources consulted for the extraction table.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

## B.3 Domain-specific Tests

### B.3.1 Attention

Table B-13 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Attention in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Conners’ Continuous Performance Test-II (CPT-II); 2000^3^ | A | A | A | A | A | A^3^ | NP^3^ | There are multiple versions of tests assessing the Continuous Performance Test (CPT) paradigm (including auditory versions). CPT is an older type of test, and several versions have been used in the neurotoxicology literature. The Conners’ version is appropriate for ages >6 years. Year of publication: This test was also published in 2004 and printed in Canada in 2006. Instructions/manual: Manual and instructions exist but are not detailed with regard to instructions. Examiner qualifications: Data were not present in the sources consulted for the extraction table. Outcomes, subscales, and subtests (all assessing aspects of attention): Most outcomes are scored using T-scores (standardized mean = 50, SD = 10). The index scores and subtests for the CPT-II have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are COPT-Hit Reaction Time, CPT-d Prime T, and CPT Hit Reaction Time (HRT) and are all normed to T-scores (standardized mean = 50, SD = 10).
Test of Everyday Attention for Children (TEA-CH); 1999 | NP^3^ | A | A | A | A | A | NP^3^ | This test is designed for children ages 6–16 years. Internal consistency: Data were not present in the sources consulted for the extraction table. Examiner qualifications: Data were not present in the sources consulted for the extraction table. Outcomes, subscale, and subtest scores: The index scores and subtests for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are Map Mission, Sky Search, and Walk/Don’t Walk, which are described below. All outcomes have standardized means of 10 and SDs of 3 and assess specific aspects of attention. Map Mission: Examinees search a visually cluttered display for target stimuli. This subtest is designed to measure selective and focused attention. Sky Search: For this subtest, the examinee circles targets on a plastic sheet while being distracted. It is designed to measure selective and focused attention. Walk/Don’t Walk: For this subtest, children listen to verbal instructions and must decide whether to move forward or not. The test includes both “go” and “no-go” paradigms and is designed to measure sustained attention and response inhibition.
Test of Variables of Attention (TOVA); 1992 | A | A | A | A | A | A | NP^3^ | This test is designed for persons aged 4–80 years. Examiner qualifications: Data were not present in the sources consulted for the extraction table. It is primarily a computer-administered test.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

* Subtests or scales within tests that belong to a different domain may be applicable to attention. These include the Developmental Neuropsychological Assessment (NEPSY): Attention domain subscale (Neuropsychological Assessment Batteries domain); Fagan Test of Infant Intelligence (FTII): Visual Attention outcome (Developmental domain); and Wechsler Memory Scale-III (WMS-III): Spatial Span Forward (Learning and Memory domain).

Table B-14 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Attention in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Conners’ Continuous Performance Test-II (CPT-II); 2000 | A | A | A | A | A | A | None.
Test of Everyday Attention for Children (TEA-CH); 1999 | D^3^ | NA | NP^3^ | NA | A | NA | Subject age (child): Some age bands had only a few participants (N = 13–30), and 1-year age bands for younger children are too wide. Population representation (child): Data were not present in the sources consulted for the extraction table.
Test of Variables of Attention (TOVA); 1992 | A | D^3^ | D^3^ | D^3^ | A | A | Subject age (adult): The norms are based on pooled samples of 1,596 individuals aged 4–80 years, of whom 1,349 were children and 250 were adults aged 20–80 years. This is a small sample for adults in a wide age range (6 age bins, the oldest of which consisted of elderly adults). Population representation (child & adult): All participants in the normative sample were from Minnesota and 99% were white.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.2 Executive Function

Table B-15 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Executive Function in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Stroop Color-Word Test; 1978/2003^3^ | NP^3^ | A | A^3^ | A | A | A^3^ | NP^3^ | Year of publication: The Golden versions of the test for adults and children were published in 1978 and 2003, respectively. This test has several versions. The Victoria version is designed for ages 18–94 years, the Golden version for ages 5–90 years, and the Trenerry version for ages 18–50 years. Internal consistency: Data were not present in the sources consulted for the extraction table. Content validity: This is an old paradigm with inherent content validity. Instructions/manual: Several versions are mentioned in the sources consulted for the extraction table. Examiner qualifications: Data were not present in the sources consulted for the extraction table.
Trail-making Test; 1944 | NP^3^ | A | A | A | A | A | NP^3^ | This is an older test developed initially for adults and later applied to children. There are multiple versions, with the Reitan version used more often in the past. There is now a child version with a manual. For these ratings, it is assumed studies are using the Reitan version. Internal consistency: The cited sources mention correlations between Parts A and B, but this is not a real reliability measure, as the two parts have different instructions and response requirements. Examiner qualifications: Data were not present in the sources consulted for the extraction table. Outcomes, domain-specific scores and subtests: There are a variety of scoring methods for this test, including pass/fail, time to completion for each of the two test forms (Pattern A and Pattern B) and/or errors on each, and differences in completion time for the two forms. The scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. They include “Pattern A” and “Pattern B,” but the actual outcomes are unclear. Both are useful for assessing the working memory aspect of executive function, although Pattern A is sometimes considered to be more of an attention test.
Verbal Fluency Test; 2001 | A | A | A | A | A | A | A | This is an older test initially developed to identify fluency deficits in aphasia. It has since been adapted as a more general test of executive function or working memory and is known more generally as the Controlled Oral Word Association Test (although Verbal Fluency Test will be used in the older literature). It is sometimes considered a test of verbal function. Norms exist for ages 8–89 years.
Wisconsin Card Sorting Test (WCST); 1993 | A | A | A | A | A | A | A | This test has multiple versions (see extraction table).

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

* Subtests or scales within tests that belong to a different domain may be applicable to executive function. These include the Developmental Neuropsychological Assessment (NEPSY): Executive function domain subscale (Neuropsychological Assessment Batteries domain); Kaufman Assessment Battery for Children (K-ABC): Mental Processing, Sequential Processing, Simultaneous Processing (IQ domain); McCarthy Scales of Children’s Abilities (MSCA) [an executive function scale is presented in the mercury literature; however, this scale is not discussed in the MSCA manual] (IQ domain); Stanford-Binet, 5th ed.: Fluid Reasoning Index, Working Memory Index (IQ domain); Wechsler Intelligence Scale for Children-R. (WISC-R): Digit span subtest (IQ domain); Wechsler Intelligence Scale for Children-III (WISC-III): Digit span subtest (IQ domain); Wechsler Intelligence Scale for Children—IV (WISC-IV): Working Memory Index (IQ domain); Wechsler Adult Intelligence Scale-III (WAIS-III): Arithmetic, digit span, and letter-number sequencing subtests (IQ domain); Wechsler Memory Scale-R (WMS-R): Spatial span (Learning and Memory domain); and Wechsler Memory Scale-III (WMS-III): Spatial span backward (Learning and Memory domain).

Table B-16 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Executive Function in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Stroop Color-Word Test; 1978/2003^3^ | NP^3^ | A^3^ | D^3^ | D^3^ | NP^3^ | A^3^ | Year of publication: The Golden versions of the test for adults and children were published in 1978 and 2003, respectively. Subject age (child): The sources consulted for the extraction table indicate no norms for children. Subject age (adult): Age bands for normative data depend on the version of the test. Some are adequate. Population representation (child & adult): The population (Canadian) is highly specific and may depend on the version used. Sample size (child): Data were not present in the sources consulted for the extraction table. Sample size (adult): Sample sizes for normative data depend on the version of the test. Some are adequate.
Trail-making Test; 1944 | NP^3^ | A | NP^3^ | A | NP^3^ | A | Norms (child): Data were not present in the sources consulted for the extraction table.
Verbal Fluency Test; 2001 | A | A | A | A | A | A | This test has multiple versions (see extraction table).
Wisconsin Card Sorting Test (WCST); 1993 | A | A | A | A | A | A | This test has multiple versions (see extraction table).

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.3 Motor Function

Table B-17 Adequacy of Factors Affecting the Reliability, Validity, and Administration Standards of Tests Used to Assess Motor Function in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Bruininks-Oseretsky Test of Motor Proficiency (BOTMP); 1978 | A | A | A | A | NP^3^ | A | A | This test is normed for ages 3–18 years. Criterion validity: Data were not present in the sources consulted for the extraction table. Highly specific outcomes are available for this test, with motor functions divided into subdomains.
Grooved Pegboard; 1963 | NA^3^ | A | A^3^ | A | A^3^ | A | NP^3^ | There are several sets of norms for this test. Those in the manual include ages 5–60 years, but other norms extend to at least age 85 (ages 20–85). This test is often scored by time instead of normative outcome. Internal consistency: This criterion is not applicable as the test involves moving pegs (all stimuli and responses are the same). Content validity: This is not discussed in the extraction table but, by definition, pegboard tests assess motor coordination (and, in this case, manual motor speed). Criterion validity: This is not presented in the extraction table, but the test outcomes predict handedness, unilateral lesions affecting motor areas, and other endpoints. Examiner qualifications: Data were not present in the sources consulted for the extraction table. Outcomes, domain-specific scores, and subtests: The scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and include mean time for each hand, a raw score based on time to completion of the task.
Movement Assessment Battery for Children (MABC); 1992 | NP^3^ | A | A | A | NP^3^ | A | A | This test is designed for children ages 4–12 years. Internal consistency: Data were not present in the sources consulted for the extraction table. Criterion validity: Data were not present in the sources consulted for the extraction table.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

* Subtests or scales within tests that belong to a different domain may be applicable to motor function. These include the Bayley Scales of Infant Development-II (BSID-II): Motor Index (Developmental domain); Denver Developmental Screening Test (DDST): Fine motor skills area and gross motor skills area outcomes (Developmental domain); Griffith Mental Development Scales (GMDS): Hand-eye Coordination Index and Locomotion Index (Developmental domain); McCarthy Scales of Children’s Abilities (MSCA): Motor Index (IQ domain); Wechsler Intelligence Scale for Children-III (WISC-III): Coding subtest (IQ domain); and Wechsler Adult Intelligence Scale-III (WAIS-III): Coding/Digit symbol subtest (IQ domain).

Table B-18 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Motor Function in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Bruininks-Oseretsky Test of Motor Proficiency (BOTMP); 1978 | A | NA | D^3^ | NA | A | NA | Population representation (child): The sample population for norms is from a small town with primarily white children.
Grooved Pegboard; 1963 | NP^3^ | A | NP^3^ | NP^3^ | NP^3^ | A | There are several sets of norms for this test. Subject age (child): According to the extraction table, norms for younger children should be used cautiously, although they exist beginning at age 5. Age bands were not present in the sources consulted for the extraction table. Population representation (child & adult): Data were not present in the sources consulted for the extraction table. Sample size (child): Data were not present in the sources consulted for the extraction table.
Movement Assessment Battery for Children (MABC); 1992 | A^3^ | NA | NP^3^ | NA | NP^3^ | NA | Subject age (child): The age bands are rather wide, especially the age band from 4 to 6 years of age. Population representation (child): Data were not present in the sources consulted for the extraction table. Sample size (child): Data were not present in the sources consulted for the extraction table.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.4 Learning and Memory

Table B-19 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Learning and Memory in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/ Manual | Examiner Qualifications | Notes
California Verbal Learning Test (CVLT); 1983, 1987 | A | A | A | A | A | A | A | The CVLT is a list learning test that includes multiple measures of learning, short- and long-term recall, recognition, free recall, and interference effects. Normative outcomes are available for persons aged 17–80 years.
California Verbal Learning Test – Children (CVLT-C); 1994 | A | A | A | A | A | A | A | The children’s version of the CVLT is structured similarly to the adult version, assessing multiple aspects of verbal learning and memory. It is designed for children ages 5 years through 16 years, 11 months.
Wechsler Memory Scale-Revised (WMS-R); 1987 | A | A | A | A | A^3^ | A | A | This test was developed for individuals ages 16–74 years. Criterion validity: The rating of adequate is based on personal knowledge of how scores on the test are associated with clinical diagnoses and specific sites of brain damage.^4^ Outcomes, domain-specific scores, and subtests: The scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. This includes Spatial Span (Working Memory), a test that has forward and backward span conditions. The outcomes for subtests such as Spatial Span are age-standardized scores (mean = 10, standard deviation [SD] = 3). Scales are calculated by summing the appropriate subtest scores and determining the appropriate age-standardized scores (mean = 100, SD = 15).
Wechsler Memory Scale-III (WMS-III); 1997 | A | A | A | A | A^3^ | A | A | This test was normed for individuals 16–89 years of age. Outcomes, domain-specific scores, and subtests: The scores for this test have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and are listed in the footnotes of evaluation tables for other domains, where applicable. This includes Spatial Span Forward (Attention) and Spatial Span Backward (Executive Function/Working Memory). The outcomes for subtests such as Spatial Span are age-standardized scores (mean = 10, SD = 3). Scales are calculated by summing the appropriate subtest scores and age-standardized scores (mean = 100, SD = 15).

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ Adequacy and deficiency are determined by the professional experience and knowledge of the co-author Dr. Roberta F. White.

* Subtests or scales within tests that belong to a different domain may be applicable to learning and memory. These include the Fagan Test of Infant Development: Visual recognition memory score (Developmental domain); McCarthy Scales of Children’s Abilities (MSCA): Memory Index (IQ domain); Stanford-Binet-4th edition.: Bead Memory test (IQ domain) [Copying Test Recall has also appeared as an outcome in the mercury literature, but this would have been a raw score adjusted for relevant variables, as the standard Copying Test does not have a recall condition and does not produce a scaled score]; and Stanford-Binet, 5th edition.: Memory Index (IQ domain).

Table B-20 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Learning and Memory in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
California Verbal Learning Test (CVLT); 1983, 1987 | NA | A | NA | D^3^ | NA | A | Population representation (adult): Normative sample subjects were drawn from only three cities in the United States.
California Verbal Learning Test – Children (CVLT-C); 1994 | NP^3^ | NA | A | NA | A | NA | Subject age (child): The sources consulted did not provide information on age bands used for the normative sample.
Wechsler Memory Scale-Revised (WMS-R); 1987 | A | A | A | A | A | A | None.
Wechsler Memory Scale-III (WMS-III); 1997 | A | A | A | A | A | A | None.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.5 Social-Emotional

Table B-21 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess the Social-Emotional Domain in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test-Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Beck Depression Inventory (BDI); 1961 | A | A | A | A | A^3^ | A^3^ | A^3^ | The extraction table indicates that the test is given to adolescents and adults but not to children. Criterion validity: It is well established that the test correlates well with other depression measures; however, these data are not present in the extraction table. Instructions/manual: Data in the extraction table come from the Spreen and Strauss text, and ratings reflect statements from that text. It was assumed that there is a test manual that could be consulted. Examiner qualifications: This is a self-administered questionnaire.
Beck Depression Inventory-Second Edition (BDI-II); 1996 | A | A | A^3^ | A | A | A^3^ | A^3^ | The age range for this test is 13–86 years. Content validity: BDI-II includes items drawn from the Diagnostic and Statistical Manual of Mental Disorders (DSM) and correlates with the Structured Clinical Interview for DSM (SCID). Instructions/manual: Data in the extraction table come from the Spreen and Strauss text, and ratings reflect statements from that text. It was assumed that there is a test manual that could be consulted. Examiner qualifications: This is a self-administered questionnaire.
Behavior Assessment System for Children, 2nd ed. (BASC-2); 2004 | A | A | A | A | A | A | A | The BASC-2 is appropriate for ages 2–25 years; however, the upper age limit not clear.
Child Behavior Checklist (CBCL); 1998 | NP^3^ | A | A | A | A^3^ | A | A^3^ | The age range for this test is not provided in the extraction table. The Child Behavior Checklist (CBCL) is appropriate for ages 2–18 years. Internal consistency: Data were not present in the sources consulted for the extraction table. Criterion validity: Criterion validity exists in other literature that was not consulted in the extraction table. Examiner qualifications: Most forms of this test are questionnaires answered by a parent, teacher, or child. There are interview and observation versions, but no data are present in the extraction table on examiner qualifications for these versions.
Children's Communication Checklist (CCC); 1998 | A | A | A | A | A | A | A^3^ | The age range for this test appears to be 5–17 years. Examiner qualifications: This is a questionnaire filled out by a parent, teacher, or clinician about the child’s behavior.
Difficulties in Emotion Regulation Scale (DERS); 2004 | A | A | A | A | A | A^3^ | A^3^ | The age range for this test appears to vary by study (see extraction table) and has included 18–55, 13–17, and 11–15 years of age. Instructions/manual: Data in the extraction table come from reliability and validity studies, and ratings reflect statements from that text. It is assumed that there is a test manual that could be consulted. Examiner qualifications: This is a self-reported measure.
Disruptive Behavior Disorders Scale (DBD); 1997 | A | A | A | A | NP^3^ | A | A^3^ | The age range for this test is unclear but may include 6–12-year-old children, preschool and school-age children, or preschool through high school children (see extraction table). Criterion validity: Data were not present in the sources consulted for the extraction table. Examiner qualifications: This is a self-reported measure filled out by parents or teachers about the child’s behavior.
Early Childhood Behavior Questionnaire; 2002 | A | A | A | A | A | A^3^ | A^3^ | The age range for this test is 18–36 months. Instructions/manual: Data in the extraction table come from reliability and validity studies, and ratings reflect statements from that text. It was assumed that there is a test manual that could be consulted, as there is a standard set of questions. Examiner qualifications: This is a parent-completed questionnaire.
EAS Temperament Survey for Children; 1984 | A | A | A | A | A | A | A^3^ | This test appears to be used for children aged 5 months to 9 years (see extraction table). Examiner qualifications: This is a parent-completed questionnaire.
Profile of Mood States (POMS); 1971^3^ | A | A | A | A | A | A | A^3^ | Norms for this test exist for ages 18 and older. Year of publication: Revisions are reported in 1992 and 2003, but a fully revised version is “under way.” Examiner qualifications: This is a standard self-reported questionnaire.
Social and Communication Disorders Checklist (SCDC); 1997 | A | A | A | A | A | A | A^3^ | The extraction table describes uses of the test at age 5 and at 2.5–17 years. Examiner qualifications: This is a parent-completed or teacher-completed questionnaire.
Social Communication Questionnaire; 2003 | A | A | A | A | A | A | A^3^ | Normative data for this test are based on persons 4–40 years of age. Examiner qualifications: This is a primary caregiver-completed questionnaire.
State-Trait Anxiety Inventory (STAI); 1966 | D^3^ | A^3^ | A | A | A^3^ | A | A | The STAI was designed for high school students, college students, and adults. There is also a child version of the test (STAI-C [not extracted]). Internal consistency: Measures of internal consistency were reported to be below the threshold of acceptable (i.e., <0.6). Test-retest reliability: Test-retest reliability appears to be Adequate for the trait anxiety measure; however, test-retest reliability is less robust for the state anxiety variable (this would be expected as state anxiety varies across circumstances and days). Criterion validity: The Adequate rating is based on information provided for sensitivity.
Strengths and Difficulties Questionnaire (SDQ); 1994 | A | A | A^3^ | A | A | A | A^3^ | The SDQ can be administered using teacher- and parent-reported answers for ages 3–16 years. For ages 11–16 years, the SDQ may be administered using self-, teacher-, and parent-reported answers. Content validity: The Adequate rating is based on factor analyses presented in the extraction table. Examiner qualifications: This is a self-administered questionnaire.
Vineland Adaptive Behavior Scales; 1998 | A | A | A | A | A | A | A | This test was designed for children aged 3 years to 18 years, 11 months.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

* Subtests or scales within tests that belong to a different domain may be applicable to social-emotional. These include the Conners’ Parent Rating Scale-Revised: Behavioral Index, Externalizing Problems, Hyperactivity Index, Oppositional Index (Clinical Conditions domain); Denver Developmental Screening Test (DDST): Social/emotional area (called Social skills in the literature) (Developmental domain); and Griffith Mental Development Scale (GMDS): Personal/Social Skills Index (Developmental domain).

Table B-22 Adequacy or Deficiency of Factors Affecting the Normative Data Standards of Psychometric Tests Used to Assess the Social-Emotional Domain in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Beck Depression Inventory (BDI); 1961 | NA | NP^3^ | NA | NP^3^ | NA | NP^3^ | Norms (adults): There is no information on normative data in the sources consulted and summarized in the extraction table.
Beck Depression Inventory-Second Edition (BDI-II); 1996 | NP^3^ | NP^3^ | D^3^ | D^3^ | D^3^ | D^3^ | Additional normative data may be available from other sources not consulted for the extraction table. Subject age (child & adult): Data on age bands are not present in the extraction table. Population representation & sample size (child & adult): The normative data are based on a convenience sample of 127 patients from one university who are not representative of the U.S. population.
Behavior Assessment System for Children, 2nd ed. (BASC-2); 2004 | A | D^3^ | A | D^3^ | A | NP^3^ | Subject age (adult): The normative sample does not report information for ages 21–25 years old—the upper age range for the test as described by the test publishers. Population representation (adult): The older age range of adults considered in the normative sample was not described. Sample size (adult): Data were not present in the sources consulted for the extraction table for ages 18–21 years.
Child Behavior Checklist (CBCL); 1998 | A^3^ | NA | A | NA | A | NA | Subject age (child): Age bands are wide for norms.
Children's Communication Checklist (CCC); 1998 | NP^3^ | NA | NP^3^ | NA | NP^3^ | NA | Data on these criteria are not provided in the sources consulted for the extraction table. The test has mainly been used in the United Kingdom and Holland (see extraction table).
Difficulties in Emotion Regulation Scale (DERS); 2004 | NA | A | NA | D^3^ | NA | A^3^ | Population representation & sample size (adult): Reliability and validity studies were carried out on convenience samples that were not representative of the population but included adolescents. The original normative sample was 357 college students ages 18–55 years.
Disruptive Behavior Disorders Scale (DBD); 1997 | NP^3^ | NA | NP^3^ | NA | NP^3^ | NA | Norms (child): Data were not present in the sources consulted for the extraction table.
Early Childhood Behavior Questionnaire; 2002 | A^3^ | NA | D^3^ | NA | D^3^ | NA | Subject age (child): Age bands were of appropriate width but did not have enough children per age band. Population representation (child): The population was not representative of the United States (90% white fathers, 95% white mothers). Sample size (child): Ten children were tested at multiple timepoints.
EAS Temperament Survey for Children; 1984 | A | NA | D^3^ | NA | D^3^ | NA | Population representation (child): Normative data were derived from small local samples. Sample size (child): Sample sizes for norms were 182 children (91 mothers) in the United States and 222 children in Holland.
Profile of Mood States (POMS); 1971 | NA | A | NA | A^3^ | NA | A | Population representation (adult): Several normative studies have been performed on adults. Population representation is considered adequate but should consider which normative sample is being used.
Social and Communication Disorders Checklist (SCDC); 1997 | NP^3^ | NA | NP^3^ | NA | NP^3^ | NA | Norms (child): Data were not present in the sources consulted for the extraction table.
Social Communication Questionnaire; 2003 | NP^3^ | NA | NP^3^ | NA | NP^3^ | NA | Norms (child): Data were not available in the sources consulted for the extraction table.
State-Trait Anxiety Inventory (STAI); 1966 | NA | D^3^ | NA | D^3^ | NA | A | Subject age (adult): Age band from 50 to 69 years of age is too wide, as age-related changes in anxiety may occur. Population representation (adult): The normative sample was not representative of the United States, where the normative study was conducted.
Strengths and Difficulties Questionnaire (SDQ); 1994 | D^3^ | NA | NP^3^ | NA | A | NA | Subject age (child): Ages 4–7 years is a wide age band for this outcome. Population representation (child): Data were not present in the sources consulted for the extraction table; normative data may be based on data sent to test authors.
Vineland Adaptive Behavior Scales; 1998 | A | NA | A | NA | A | NA | None.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.6 Verbal/Language

Table B-23 Adequacy of Factors Affecting the Reliability, Validity, and Administration Standards of Tests Used to Assess Verbal/Language Abilities in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test- Retest | Content | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Boston Naming Test (BNT); 1978^3^ | A | NP^3^ | A | A | A^3^ | A^3^ | NP^3^ | Year of publication: This test was also published in 1978. Age range for the test is not stated in the extraction table but is believed to be 6–85 years. Test-retest reliability: Data were not present in the sources consulted for the extraction table. Criterion validity: Poor test performance is associated with a number of neurological disorders (e.g., aphasic syndromes, Alzheimer’s disease, frontal dementia) and with diagnosed verbal learning problems in children.^4^ Examiner qualifications: Data were not present in the sources consulted for the extraction table, although it is usually administered by speech pathologists and neuropsychologists.^4^
Boston Naming Test-2 (BNT-2); 2001 | A | A^3^ | A | A | A | A | NP^3^ | The age range for the test is 5–13 years and 18 years and older. Test-retest reliability: This is rated as adequate given data from adults. Examiner qualifications: Data were not present in the sources consulted for the extraction table, but this test is generally administered by psychologists and speech pathologists.^4^
MacArthur-Bates Communicative Development Inventories (CDI); 1993 | A | A | A | A | A | A^3^ | NP^3^ | This test is normed for children 8–30 months of age. Instructions/manual: Data in the extraction table come from validation papers, and ratings reflect statements from these papers. There is a test manual. Examiner qualifications: The test has direct testing versions and a parent-report version. Data were not present in the sources consulted for the extraction table.
Peabody Picture Vocabulary Test-Revised (PPVT-R); 1981 | A | A | A | A | A | A | A | The age range for this test is 2.5–40 years of age.
Peabody Picture Vocabulary Test-III (PPVT-III); 1997 | A | A | A | A | A | A | A | The age range for the PPVT-III is 2.5–90+ years of age.
Preschool Language Scales-3 (PLS-3); 1969^3^ | NP^3^ | A | A | A | A | A | NP^3^ | This test is designed for children ages 2 weeks to 6 years. Year of publication: This test was also published in 1979 and 1992. Internal consistency: Data were not present in the sources consulted for the extraction table. Examiner qualifications: Data were not present in the sources consulted for the extraction table. The scores for this test that have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg are all verbal and include: Auditory Comprehension, Expressive Communication (formerly named Verbal Ability), and Total Language. All are scored with a standardized mean of 100 and standard deviation (SD) of 15.
Speech and Language Assessment Scale (SLAS); 1989 | NP^3^ | NP^3^ | A | A | A | A | A^3^ | This is a parent-report test of speech and language that assesses children 3–5 years of age. Internal consistency: Data were not present in the sources consulted for the extraction table. Test-retest reliability: Data were not present in the sources consulted for the extraction table. Examiner qualifications: This is a parent-completed questionnaire on speech.
Test of Language Development (TOLD); 1977^3^ | A | NP^3^ | A | A | A^3^ | A | A | This test applies to ages 4–9 years. Year of publication: This test was also published in 1978. Test-retest reliability: Data were not present in the sources consulted for the extraction table. The scores for this test that have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg are all measures of verbal function and include: Grammar Completion, Grammar Understanding, Oral Vocabulary, Picture Vocabulary, and Sentence Imitation. All subtests are scored with a standardized mean of 10 and SD of 3.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

^4^ Adequacy and deficiency are determined by the professional experience and knowledge of the co-author Dr. Roberta F. White.

* Subtests or scales within tests that belong to a different domain may be applicable to verbal/language. These include the Denver Developmental Screening Test (DDST): Communication area (Developmental domain); Griffith Mental Development Scale (GMDS): Hearing and Speech Index (Developmental domain); Kaufman Brief Intelligence Test (K-BIT): The Verbal Intelligence score is equivalent to Vocabulary Performance (IQ domain); McCarthy Scales of Children’s Abilities (MSCA): Verbal Index (IQ domain); Stanford-Binet, 5th edition: Knowledge Index (IQ domain); Wechsler Intelligence Scale for Children-R (WISC-R): Verbal IQ, Similarities subtest (IQ domain); Wechsler Intelligence Scale for Children-III (WISC-III): Verbal IQ, Information subtest, Vocabulary subtest (IQ domain); Wechsler intelligence Scale for Children-IV (WISC-IV): Verbal Comprehension Index (IQ domain); Wechsler Preschool and Primary Scale of Intelligence-Revised (WPPSI-R): Verbal IQ (IQ domain); Wechsler Adult Intelligence Scale—III (WAIS-III): Vocabulary subtest, Similarities subtest, Comprehension subtest (IQ domain); Griffith Mental Development Scales (GMDS): Hearing and Speech (Developmental domain); and Denver Developmental Screening Test (DDST): Communication (language) area (Developmental domain).

Table B-24 Adequacy of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Verbal/Language Abilities in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Boston Naming Test (BNT); 1978 | D^3^ | A^3^ | NP^3^ | NP^3^ | D^3^ | D^3^ | Subject age (child): Child norms are based on a very small sample size. Subject age (adult): Age bins for adults are in 5-year increments. Population representation (child & adult): Data were not present in the sources consulted for the extraction table. Sample size (child & adult): Sample sizes for both children and adults are described as small in the extraction table.
Boston Naming Test-2 (BNT-2); 2001 | D^3^ | A | NP^3^ | A^3^ | NP^3^ | A^3^ | Subject age (child): In the sources consulted for the extraction table, norms were presented for ages 6–12.5 years only and appeared to be outdated. Population representation (child): Data were not present in the sources consulted for the extraction table. Population representation (adult): The characterization of population representation in adults is not detailed, but it appears to be adequate. Sample size (child): Data were not present in the sources consulted for the extraction table. Sample size (adult): Several adult normative samples exist, with one consisting of 663 participants and another of 1,000 participants (see extraction table).
MacArthur-Bates Communicative Development Inventories (CDI); 1993 | A | NA | NP^3^ | NA | NP^3^ | NA | Population representation & sample size (child): Data were not present in the sources consulted for the extraction table. However, it was noted that the test has been used in several different countries.
Peabody Picture Vocabulary Test-Revised (PPVT-R); 1981 | A | D^3^ | A | D^3^ | A | A | Subject age (adult): Normative sample limited to ages 18 or 19 to 40 years. Population representation (adult): Adult participants do not appear to be representative.
Peabody Picture Vocabulary Test-III (PPVT-III); 1997 | A | A | A | A | A | A | None.
Preschool Language Scales-3 (PLS-3); 1969 | A | NA | A | NA | A | NA | None.
Speech and Language Assessment Scale (SLAS); 1989 | NP^3^ | NA | NP^3^ | NA | NP^3^ | NA | Norms (child): Data were not present in the sources consulted for the extraction table.
Test of Language Development (TOLD); 1977 | NP^3^ | NA | NP^3^ | NA | A | NA | Subject age (child): The sources consulted for the extraction table did not provide information on age bands used in the normative data. Population representation (child): Data were not present in the sources consulted for the extraction table.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.7 Visuospatial Function

Table B-25 Adequacy or Deficiency of Factors Affecting the Reliability, Validity, and Administration Standards of Psychometric Tests Used to Assess Visuospatial Function in Developmental Neurotoxicity Studies^1,2^

Test*; Year of Publication | Reliability | | | Validity | | | Administration | | Notes
Test*; Year of Publication | Internal Consistency | Test- Retest | Content | | Construct | Criterion | Instructions/Manual | Examiner Qualifications | Notes
Bender Visual-Motor Gestalt Test; 1938 | A | A | A | | A | A^3^ | A | NP^3^ | This test has been administered to children 2.5 years through adulthood. Criterion validity: The extraction table does not reflect existing data on the test’s association with known brain damage and certain developmental disorders. Examiner qualifications: Data were not present in the sources consulted for the extraction table. Outcomes, subscale, and subtest scores: The scores for this test that have been identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg are copy and recall. It is assumed that raw scores were used as true normative scores do not exist for this version of the Bender.
Bender Visual-Motor Gestalt-Test II; 2003 | A | A | A | | A^3^ | A | A | NP^3^ | This test has versions for 4 years, 11 months through 85+ years. Construct validity: This test has inherent construct validity as a test of visuo-constructive ability and its relationship to the initial Bender Gestalt test. Correlations with IQ and other tests listed in the extraction table are not high; this is not an indictment of the test, as it measures a specific ability and not general intelligence. Examiner qualifications: Data were not present in the sources consulted for the extraction table.
Developmental Test of Visual-Motor Integration (VMI); 1967^3^ | A | A | A^3^ | | A | A^3^ | A | A | This test is used with children age 2.5 and adults. Year of publication: This test was restandardized in 1982 and 1989. Content validity: This test has inherent construct validity given its stimuli and task demands. Criterion validity: The reported predictive validity was used to determine an Adequate rating for criterion validity. This test is a predictor of verbal/performance discrepancies on IQ tests in children with nonverbal learning disabilities.
Finger Identification Test; 1959^3^ | A | A | A^3^ | | A^3^ | NP^3^ | A^3^ | NP^3^ | This test can be administered to ages 6 years through adulthood. Year of publication: The test was also published in Contributions to Neuropsychological Assessment, 1983. The test was developed to assess a highly specific aspect of brain dysfunction associated with the left posterior portion of the brain. Finger identification is called finger gnosis (or finger agnosia when referring to deficits in finger naming). Content validity: Finger agnosia is a specific and localized neurological function. Therefore, by definition, the test has content validity. Construct validity: Data reported in the extraction table indicate that performance is associated with reading and predictive of subsequent reading achievement, and reading is localized in the same brain area as finger naming. The poor correlations with finger dexterity do not argue against the test’s validity, as this function is controlled by different brain areas. Criterion validity: Data were not present in the sources consulted for the extraction table. Instructions/manual: Data in the extraction table come from text Strauss and Lezak, and ratings reflect statements from that text. Lezak indicates that there is a test manual (Lezak et al. 2004; Strauss et al. 2006). Examiner qualifications: Data were not present in the sources consulted for the extraction table.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

* Subtests or scales within tests that belong to a different domain may be applicable to visuospatial function. These include K-BIT: Nonverbal intelligence outcome represents score on the Matrices test, a test of visuospatial reasoning (IQ domain); Bayley Scale of Infant Development-II (BSID-II): Psychomotor Index (Developmental domain); Griffith Mental Development Scale (GMDS): Hand-eye Performance Index (Developmental domain); McCarthy Scales of Children’s Abilities (MSCA): Perceptual Index (IQ domain); Stanford-Binet Intelligence Test, 4^th^ edition: Copying test (IQ domain); Stanford-Binet Intelligence Test, 5^th^ edition: Visual-spatial Processing Index (IQ domain); Wechsler Intelligence Scale for Children-R: Performance IQ, Block Design subtest (IQ domain) [“Visuospatial performance” was identified in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg and is likely Performance IQ and not a separate measure, at least it is not a WISC-R measure with that name]; Wechsler Intelligence Scale for Children-III (WISC-III): Performance IQ, Block Design test (IQ domain); Wechsler Intelligence Scale for Children-IV (WISC-IV): Perceptual Reasoning Index (IQ domain); Wechsler Preschool and Primary Scale of Intelligence-R (WPPSI-R): Performance IQ (IQ domain); Wechsler Adult Intelligence Scale-Revised (WAIS-R): Block Design subtest (IQ domain); Wechsler Adult Intelligence Scale-III (WAIS-III): Block Design subtest, Picture Completion subtest, Object Assembly subtest, Picture Arrangement subtest, Matrix Reasoning subtest (sometimes classified as executive function) (IQ domain); and Fagan Test of Infant Intelligence (FTII): Visual Recognition (Developmental domain).

Table B-26 Adequacy or Deficiency of Factors Affecting the Normative Data of Psychometric Tests Used to Assess Visuospatial Function in Developmental Neurotoxicity Studies^1,2^

Test; Year of Publication | Normative Data | | | | | | Notes
Test; Year of Publication | Subject Age | | Population Representation | | Sample Size | | Notes
Test; Year of Publication | Children | Adults | Children | Adults | Children | Adults | Notes
Bender Visual-Motor Gestalt Test; 1938 | NP^3^ | D^3^ | D^3^ | D^3^ | D^3^ | D^3^ | This is an older test, and raw scores were used as outcomes when this test was used historically (it was later revised into Bender Gestalt II). There are no norms in the usual sense of the term. However, the manual presents typical drawings produced by children for each year of age from 3 to 11 years and 11 years through adulthood (see extraction table). Subject age (child): Age-specific norms were not present in the sources consulted for the extraction table. Subject age (adult): Outcomes for age 11 years through adulthood are not parsed into bins. Population representation & sample size (child & adult): True normative data were not collected with now current sampling strategies.
Bender Visual-Motor Gestalt-Test II; 2003 | A | A | A | A | A | A | None.
Developmental Test of Visual-Motor Integration (VMI); 1967^3^ | A^3^ | D^3^ | A | D^3^ | A | D^3^ | Year of publication: Test was restandardized in 1982 and 1989. Subject age (child): For children, the newer norms are Adequate for age and population representation through age 14 years. Subject age, population representation, and sample size (adult): The test author suggests that norms for age 14 can be used to assess test results in older adolescents and adults. Adults are not well represented in norms.
Finger Identification Test; 1959^3^ | A | A | NP^3^ | NP^3^ | D^3^ | D^3^ | Year of publication: The test was also published in Contributions to Neuropsychological Assessment, 1983. Population representation (child & adult): Data were not present in the sources consulted for the extraction table. Sample size (child & adult): The sample size utilized for this test appears to be small.

^1^ A: adequate, D: deficient, NP: not present in test manuals or other materials reviewed, NA: not applicable.

^2^ Adequacy and deficiency are defined based on the criteria described in Part 1 of this document.

^3^ See Notes column.

### B.3.8 Processing Speed

No tests assessing processing speed were identified in the epidemiological studies from the in-progress EPA IRIS toxicological review of MeHg.

Subtests or scales within tests that belong to a different domain may be applicable to processing speed. These include Wechsler Intelligence Scale for Children III (WISC III): Processing Speed Index (measures speed in processing visual material) (IQ domain); Wechsler intelligence Scale for Children-IV (WISC-IV): Processing Speed Index (IQ domain); Wechsler Adult Intelligence Scale-III (WAIS-III): Processing Speed Index. (IQ domain); and Conners’ Continuous Performance Test-II (CPT-II): Hit Reaction Time (Attention domain).