# Appendix A Psychometric Tests Considered for Evaluation

## A.1 Psychometric Tests Included for Evaluation

Table A-1 lists the neurodevelopmental domains in alphabetical order and their associated psychometric tests. The evaluation ratings and notes for each test are detailed in Appendix B, where they are sorted by test type and domain.

Table A-1 Psychometric Tests Included for Evaluation by Domain

Domain | Test Name
Academic Achievement | KeyMath Diagnostic Arithmetic Test^4^
Academic Achievement | KeyMath Diagnostic Arithmetic Test-Revised (KeyMath R)^4^
Academic Achievement | Wechsler Individual Achievement Test (WIAT)^6^
Academic Achievement | Woodcock-Johnson III Test of Achievement (WJ III ACH)^1^
Attention | Conners’ Continuous Performance Test-II (CPT-II)^1^
Attention | Test of Everyday Attention for Children (TEA-CH)^4^
Attention | Test of Variables of Attention (TOVA)^4^
Clinical Conditions | Autism Spectrum Quotient (AQ)^6^
Clinical Conditions | Barkley Adult ADHD Rating Scale-IV^6^
Clinical Conditions | Childhood Asperger’s Syndrome Test (CAST)^6^
Clinical Conditions | Childhood Autism Rating Scale (CARS)^6^
Clinical Conditions | Conners’ Parent Rating Scale-Revised (CPRS-R)^1^
Clinical Conditions | Conners’ Teacher Rating Scale-Revised (CTRS-R)^1^
Clinical Conditions | Spence Children’s Anxiety Scale (SCAS)^6^
Developmental | Bayley Scales of Infant Development (BSID-1)^4^
Developmental | Bayley Scales of Infant Development, Second edition (BSID-II)^2^
Developmental | Bayley Scales of Infant Development-III (BSID-3)^6^
Developmental | Brazelton Newborn Assessment Scale (NBAS)^6^
Developmental | Denver Development Screening Test (DDST)^6^
Developmental | Denver Development Screening Test-II (DDST II)^6^
Developmental | Fagan Test of Infant Intelligence^6^
Developmental | Gesell Developmental Schedules^6^
Developmental | Griffith Mental Development Scales (GMDS)^6^
Developmental | Kyoto Scale of Psychological Development (KSPD; K-test)^6^
Developmental | Neonatal Intensive Care Unit Network Neurobehavioral Scale (NNNS)^6^
Developmental | Prechtl General Movement Assessment (GMA)^6^
Executive Function | Stroop Color-Word Test^4^
Executive Function | Trail-making Test^4^
Executive Function | Verbal Fluency Test^5^
Executive Function | Wisconsin Card Sorting Test (WCST)^2^
General Intelligence/IQ | Kaufman Assessment Battery for Children (K-ABC)^4^
General Intelligence/IQ | Kaufman Brief Intelligence Test (K-BIT)^4^
General Intelligence/IQ | McCarthy Scales of Children’s Abilities (MSCA)^2^
General Intelligence/IQ | Raven’s Coloured Progressive Matrices (Raven’s CPM)^2^
General Intelligence/IQ | Raven’s Standard Progressive Matrices (Raven’s SPM)^2^
General Intelligence/IQ | Stanford-Binet Intelligence Scale: Fourth Edition (S-B 4)^2^
General Intelligence/IQ | Stanford-Binet Intelligence Scale: Fifth Edition (S-B 5)^2^
General Intelligence/IQ | Wechsler Intelligence Scale for Children (WISC)^6^
General Intelligence/IQ | Wechsler Intelligence Scale for Children-Revised (WISC-R)^2^
General Intelligence/IQ | Wechsler Intelligence Scale for Children-III (WISC-III)^1^
General Intelligence/IQ | Wechsler Intelligence Scale for Children-IV (WISC-IV)^2^
General Intelligence/IQ | Wechsler Preschool and Primary Scale of Intelligence-Revised (WPPSI-R)^1^
General Intelligence/IQ | Wechsler Adult Intelligence Scale-Revised (WAIS-R)^2^
General Intelligence/IQ | Wechsler Adult Intelligence Scale-III (WAIS-III)^2^
Learning and Memory | California Verbal Learning Test (CVLT)^2^
Learning and Memory | California Verbal Learning Test – Children (CVLT-C)^4^
Learning and Memory | Wechsler Memory Scale-Revised (WMS-R)^2^
Learning and Memory | Wechsler Memory Scale-III (WMS-III)^2^
Mental Status | Mini-Mental State Examination (MMSE)^5^
Motor Function | Bruininks-Oseretsky Test of Motor Proficiency (BOTMP)^6^
Motor Function | Grooved Pegboard^4^
Motor Function | Movement Assessment Battery for Children (MABC)^6^
Neuropsychological Assessment Batteries | Developmental Neuropsychological Assessment (NEPSY)^2^
Neuropsychological Assessment Batteries | Neurobehavioral Evaluation System (NES)^6^
Social-Emotional | Beck Depression Inventory (BDI)^4^
Social-Emotional | Beck Depression Inventory-Second Edition (BDI-II)^4^
Social-Emotional | Behavior Assessment System for Children, 2nd ed. (BASC-2)^1^
Social-Emotional | Child Behavior Checklist (CBCL)^4^
Social-Emotional | Children's Communication Checklist (CCC)^6^
Social-Emotional | Difficulties in Emotion Regulation Scale (DERS)^6^
Social-Emotional | Disruptive Behavior Disorders Scale (DBD)^6^
Social-Emotional | Early Childhood Behavior Questionnaire^6^
Social-Emotional | EAS Temperament Survey for Children^6^
Social-Emotional | Profile of Mood States (POMS)^2^
Social-Emotional | Social and Communication Disorders Checklist (SCDC)^6^
Social-Emotional | Social Communication Questionnaire^6^
Social-Emotional | State-Trait Anxiety Inventory (STAI)^3^
Social-Emotional | Strengths and Difficulties Questionnaire (SDQ)^3^
Social-Emotional | Vineland Adaptive Behavior Scales^5^
Verbal/Language | Boston Naming Test (BNT)^4^
Verbal/Language | Boston Naming Test-2 (BNT-2)^4^
Verbal/Language | MacArthur-Bates Communicative Development Inventories (CDI)^6^
Verbal/Language | Peabody Picture Vocabulary Test-Revised (PPVT-R)^2^
Verbal/Language | Peabody Picture Vocabulary Test-III (PPVT-III)^2^
Verbal/Language | Preschool Language Scales-3 (PLS-3)^1^
Verbal/Language | Speech and Language Assessment Scale (SLAS)^6^
Verbal/Language | Test of Language Development (TOLD)^6^
Visuospatial Function | Bender Visual-Motor Gestalt Test^2^
Visuospatial Function | Bender Visual-Motor Gestalt Test II^2^
Visuospatial Function | Developmental Test of Visual-Motor Integration (VMI)^4^
Visuospatial Function | Finger Identification Test^4^

^1^ Test information was obtained from manuals only.

^2^ Test information was obtained from manuals and academic textbooks.

^3^ Test information was obtained from manuals and peer-reviewed literature.

^4^ Test information was obtained from academic textbooks only.

^5^ Test information was obtained from academic textbooks and peer-reviewed literature.

^6^ Test information as obtained from peer-reviewed literature only.

## A.2 Psychometric Tests Excluded from Extraction and Evaluation

Table A-2 lists the psychometric tests that were excluded from the extraction and evaluation process and the reason for exclusion.

Table A-2 Psychometric Tests Excluded from Evaluation^1^

Reason for Exclusion from Evaluation | Test Name
Idiosyncratic^2^ | Aberrant Behavior Checklist
Idiosyncratic^2^ | Ages & Stages Communication Scale (Parent Assessment)
Idiosyncratic^2^ | Ameil-Tyson and Gosselin Exam
Idiosyncratic^2^ | Audiometric evaluation using Modified Hughson-Westlake Procedure
Idiosyncratic^2^ | Autism Diagnostic Interview-Revised
Idiosyncratic^2^ | Autism Diagnostic Observation Schedules (Revised & Generic)
Idiosyncratic^2^ | Autism Treatment Evaluation Checklist for Parents
Idiosyncratic^2^ | Burt Recognition Test
Idiosyncratic^2^ | Burt Recognition Test-Revised
Idiosyncratic^2^ | Cambridge Neuropsychological Test Automated Battery (CANTAB)
Idiosyncratic^2^ | Clinical Global Impression-Severity Scale
Idiosyncratic^2^ | Comprehensive Developmental Inventory for Infants & Toddlers (CDIIT)
Idiosyncratic^2^ | Cook-Medley Hostility Index-Youth Version
Idiosyncratic^2^ | Dale & Bishop Grammar Rating
Idiosyncratic^2^ | Delayed Spatial Alternation Test
Idiosyncratic^2^ | Everts Behavior Rating Scale
Idiosyncratic^2^ | Go/No-Go Response Inhibition Paradigm
Idiosyncratic^2^ | Healthy Behavior Questionnaire
Idiosyncratic^2^ | Huttenlocher Motor Tasks
Idiosyncratic^2^ | Infant Behavior Questionnaire
Idiosyncratic^2^ | Infant Behavior Questionnaire-Revised
Idiosyncratic^2^ | Test of Attentional Performance for Children (KITAP)
Idiosyncratic^2^ | Localisation of Tactile Stimuli Test
Idiosyncratic^2^ | Mullen Scales of Early Learning
Idiosyncratic^2^ | Neurobehavioral Core Test Battery
Idiosyncratic^2^ | Neurological Examination for Subtle Signs
Idiosyncratic^2^ | Parent’s Evaluation of Developmental Status
Idiosyncratic^2^ | Sheriden Gardiner Letter Matching Test
Idiosyncratic^2^ | Social Responsiveness Scale
Idiosyncratic^2^ | Static Motor Steadiness Test
Idiosyncratic^2^ | Stycar Miniature Toy Test
Idiosyncratic^2^ | Test of Haptic Matching
Idiosyncratic^2^ | Toddler Temperament Scale
Insufficient information^3^ | A-not-B Test
Insufficient information^3^ | Abnormal and Repetitive Behavior Scale
Insufficient information^3^ | Children’s Category Test
Insufficient information^3^ | Clay Diagnostic Survey
Insufficient information^3^ | Conner’s Continuous Performance Test (CCPT)
Insufficient information^3^ | Differential Reinforcement of Low Rate Schedules
Insufficient information^3^ | Frontal Assessment Battery
Insufficient information^3^ | Halstead-Reitan Battery
Insufficient information^3^ | Hong Kong List Learning Test
Insufficient information^3^ | Neurobehavioral Evaluation System (NES2)
Insufficient information^3^ | Neurobehavioral Evaluation System (NES3)
Insufficient information^3^ | Santa Ana Form Board
Insufficient information^3^ | Social Maturity Scale
Insufficient information^3^ | Twenty Statements about Language-Related Difficulties List
Insufficient information^3^ | Visual Expectation Paradigm
Insufficient information^3^ | Visual Recognition Memory (VRM) Paradigm
Insufficient information^3^ | Wide Range Assessment of Memory and Learning
Insufficient information^3^ | Wide Range of Assessment of Visual-Motor Abilities
Insufficient information^3^ | Woodcock-Johnson Test of Achievement (W-J-II)
Insufficient information^3^ | WPS Electronic Tapping Test

^1^ Test names appear primarily as they are reported in studies included in the epidemiological literature for the in-progress EPA IRIS toxicological review of MeHg. Additional variations of test names may be utilized in the neuropsychology literature.

^2^ Tests were categorized as idiosyncratic if they appeared in a single publication considered in the in-progress EPA Toxicological review of Methylmercury, were used only in a specific population, and/or were used in a study that was not conducive to dose-response analysis (n = 33).

^3^ Tests were categorized as having insufficient information if no manual was available and secondary sources, including peer-reviewed literature, did not provide enough information to assess a majority of the evaluation principles (n = 20).