# NTP Board of Scientific Counselors Review

The NTP carefully considered the external peer reviewer comments in preparing the NTP Monograph on the State of the Science Concerning Fluoride Exposure and Neurodevelopmental and Cognitive Health Effects: A Systematic Review with a target date for release of May 18, 2022 (hereafter called the May 2022 NTP Monograph). The NTP Director, Rick Woychik, Ph.D., decided to delay publication of the May 2022 NTP Monograph so that it could undergo additional review prior to publication. In May 2022, the NTP Director asked the chair of the NTP Board of Scientific Counselors (BSC) to review NTP’s responses to comments received from external peer reviewers and federal agencies. The BSC Chair and the NTP Director then jointly made the decision to convene an independent working group of subject-matter experts (Table 1.1 of the BSC Working Group [WG] report) to conduct this review and report its findings to the BSC. An additional round of interagency review of the May 2022 NTP Monograph was conducted. The NTP prepared responses to all comments received and carefully considered the comments from federal agencies in preparing the September 2022 NTP Monograph which were submitted to the BSC for review.

The BSC Working Group (BSC WG) was charged to evaluate the adequacy of the NTP authors’ responses to external peer review and/or federal agency comments received during development of the State of the Science Monograph and the Meta-Analysis Manuscript. They were not charged to provide independent peer review of the September 2022 NTP Monograph or Meta-Analysis Manuscript. However, the BSC WG was asked to provide perspectives and suggest revisions that might improve the quality of either document based on reviewers’ comments and on NTP authors’ responses to those comments.

In a public meeting on May 4, 2023, the BSC WG presented its report (https://ntp.niehs.nih.gov/sites/default/files/2023-04/wgrptBSC20230400.pdf) on the September 2022 NTP Monograph to the BSC. Overall, the BSC WG agreed with most (87%) of the NTP authors’ responses to reviewers’ comments (283/325). For the 42 responses that the BSC WG considered inadequate, they recommended revisions. In addition, the BSC WG identified a subset of these as 9 recurring issues for which they issued 9 global recommendations. The BSC WG rated the NTP authors’ responses to the reviewer comments as follows:

- 232 reviewer comments where NTP authors’ responses rated adequate; no edits suggested.
- 51 reviewer comments where NTP authors’ responses rated adequate; edits suggested.
- 42 reviewer comments where NTP authors’ responses rated inadequate; revisions recommended.

After deliberations and discussion, the BSC voted to accept the BSC WG report in full, with the condition of one correction, and encouraged the NTP to not delay publication of this important document any further. The BSC accepted the BSC WG report at a meeting on May 16, 2023.

The NTP authors responded to the BSC WG comments and carefully considered suggested edits and recommendations in finalizing this monograph. As part of the edits, the NTP authors added an Addendum in response to a request from the BSC WG to update the literature assessing fluoride exposures and children’s IQ to match the timeframe for literature included in a companion systematic review and meta-analysis, which is a separate peer-reviewed journal publication (DTT Meta-analysis, Taylor et al. 2024, in press).^1^

1 The NTP authors of this monograph conducted a companion systematic review and meta-analysis of fluoride exposure and children’s IQ. Reference to this meta-analysis is cited in this monograph as “(DTT Meta-analysis, Taylor et al. 2024, in press).”

## BSC Working Group Members

- David L. Eaton, Ph.D., DABT, FATS (Chair)*
  Emeritus Professor, University of Washington
  Adjunct Professor of Pharmacology and Toxicology, University of Arizona
  *BSC Chair until December 31, 2022; remained as BSC Working Group Chair
- Antonia M. Calafat, Ph.D.
  Chief, Organic Analytical Toxicology Branch
  Division of Laboratory Sciences
  National Center for Environmental Health
  Centers for Disease Control and Prevention (CDC)
- Pamela Den Besten, D.D.S., M.S.
  Professor, Department of Orofacial Sciences
  School of Dentistry
  University of California San Francisco
- Stephanie M. Engel, Ph.D.
  Professor, Department of Epidemiology
  Director, Center for Early Life Exposures and Neurotoxicity
  Deputy Director, Center for Environmental Health and Susceptibility
  Gillings School of Global Public Health
  University of North Carolina Chapel Hill
- Michael K. Georgieff, M.D.
  Executive Vice Chair and Martin Lenz Harrison Land Grant
  Professor, Department of Pediatrics
  Director, Center for Neurobehavioral Development
  Co-Director, Masonic Institute for the Developing Brain
  University of Minnesota Medical School
- Matthew J. Maenner, Ph.D.
  Chief, Child Development and Disability Branch
  Division of Human Development and Disability
  National Center on Birth Defects and Developmental Disabilities
  Centers for Disease Control and Prevention (CDC)
- David Michaels, Ph.D., M.P.H.*
  Professor
  Department of Environmental and Occupational Health
  The Milken School of Public Health
  George Washington University
  *BSC member until December 31, 2022; remained on BSC Working Group
- Sally C. Morton, Ph.D., M.Sc.
  Executive Vice President
  Knowledge Enterprise
  Professor, College of Health Solutions and School of Mathematical and Statistical Sciences
  Arizona State University
- Sharon K. Sagiv, Ph.D., M.P.H.
  Associate Adjunct Professor, Division of Epidemiology and Biostatistics
  Investigator, Center for Environmental Research and Children’s Health
  School of Public Health
  University of California, Berkeley
- Ian J. Saldanha, M.B.B.S., Ph.D., M.P.H.
  Associate Professor, Center for Clinical Trials and Evidence Synthesis, Department of Epidemiology
  Johns Hopkins Bloomberg School of Public Health
  Adjunct Associate Professor, Department of Health Services Policy and Practice
  Brown University School of Public Health