# About This Monograph

## What This Monograph Does

This Monograph and Addendum evaluate the evidence of an association between exposures to fluoride and human neurodevelopment and cognition.

The Monograph is a systematic review of human, experimental animal, and mechanistic studies that focuses on human data because it is the most informative from available studies. Findings from human epidemiology studies published through May 1, 2020, are evaluated and summarized in the main text. This includes studies of various cognitive neurodevelopmental endpoints in children, a limited number of studies in adults, and studies of potential mechanisms. The majority of the studies examine intelligence quotients (IQs) of children with higher estimates of fluoride exposure compared to children with lower estimates of fluoride exposure.

The human studies reviewed in this Monograph and Addendum involve fluoride exposures from many sources including drinking water, prepared beverages, foods, and dental products.

The children’s IQ studies discussed in the Monograph and Addendum were performed in 10 countries including Mexico and Canada. No studies evaluating IQ were conducted in the United States.

## What Evidence Was Evaluated

Published research from human, experimental animal, and mechanistic studies on fluoride exposure and neurodevelopment and cognition was identified and evaluated. Studies from each evidence stream were fully evaluated through April 1, 2019. In early drafts, it was apparent that the animal data were of poor quality and that the human data were most informative and would be the basis of the confidence conclusions. Therefore, findings from the animal evidence stream were determined to be inadequate and were removed from further drafts. Mechanistic evidence from animal studies was retained in Appendix F. The epidemiology data were updated and fully assessed through May 1, 2020, for the current Monograph, and the animal and mechanistic literature identified between April 1, 2019, and May 1, 2020, were scanned for potentially major advances that might impact the confidence conclusions. This effort did not find significant evidence of increased understanding of how fluoride may affect children’s cognitive neurodevelopment and did not strengthen the confidence assessment based on the human evidence available in 2020.

Considerable time elapsed during peer reviews of drafts of this Monograph necessitating an updated search of the children’s IQ and associated mechanistic literature through October 2023, carried out according to the same systematic review procedures. To accommodate the review, this update is summarized in an Addendum following the conclusion of the main text of this Monograph. The systematic review of the updated literature did not result in a change to the earlier moderate confidence conclusion. The experimental animal and mechanistic literature were also searched and added to updated, interactive reference flow diagrams in the Addendum for transparency.

## What This Monograph Does Not Do

This Monograph and Addendum do not address whether the sole exposure to fluoride added to drinking water in some countries (i.e., fluoridation, at 0.7 mg/L in the United States and Canada) is associated with a measurable effect on IQ.

This Monograph and Addendum do not provide a quantitative estimate of the number of IQ points lost for a given increase in fluoride exposure measures; however, references are provided to prior and concurrent meta-analyses that do provide such estimates (DTT Meta-analysis, Taylor et al. 2024, in press).

This Monograph and Addendum do not assess benefits of the use of fluorides in oral health or provide a risk/benefit analysis.