# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the monograph entitled Draft NTP Monograph on the State of the Science Concerning Fluoride Exposure and Neurodevelopmental and Cognitive Health Effects: A Systematic Review by letter in December 2021. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Comment on the technical accuracy and whether the monograph entitled Draft NTP Monograph on the State of the Science Concerning Fluoride Exposure and Neurodevelopmental and Cognitive Health Effects: A Systematic Review is clearly stated and objectively presented.
2. Determine whether the scientific evidence supports the NTP’s confidence ratings for the bodies of evidence regarding neurodevelopmental and cognitive health effects associated with exposure to fluoride.

NTP carefully considered reviewers’ comments in finalizing this monograph.

## Peer Reviewers

- Ethan Balk, M.D., M.P.H.
  Associate Professor (Research)
  Brown University School of Public Health
  Providence, Rhode Island, USA
- Pam Factor-Litvak, Ph.D.
  Professor of Epidemiology
  Columbia University Medical Center
  New York, New York, USA
- Erin Haynes, Dr.P.H.
  Kurt W. Deuschle Professor in Preventive Medicine and Environmental Health
  University of Kentucky College of Public Health
  Lexington, Kentucky, USA
- Julie Obbagy, Ph.D., R.D.
  Nutritionist, Center for Nutrition Policy and Promotion
  Office of Nutrition Guidance and Analysis
  U.S. Department of Agriculture
  Medfield, Massachusetts, USA
- Heather Volk, Ph.D.
  Associate Professor
  Johns Hopkins Bloomberg School of Public Health
  Baltimore, Maryland, USA