# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Developed protocol and conducted systematic review through oversight and review of literature search, screening, data extraction, and risk-of-bias assessment; wrote and edited monograph
  Kyla W. Taylor, Ph.D., Project Lead
  John R. Bucher, Ph.D.
  Andrew A. Rooney, Ph.D.
- ICF, Reston, Virginia, USA
  Conducted literature screening, data extraction, and risk-of-bias assessment; reviewed data, results, and analyses; wrote, edited, and formatted monograph; provided database and HAWC support
  Robyn B. Blain, Ph.D.
  Sorina E. Eftim, Ph.D.
  Kristen Magnuson, M.E.S.M., Deputy Work Assignment Manager
  Christopher A. Sibrizzi, M.P.H., Lead Work Assignment Manager
- Conducted literature screening, data extraction, and risk-of-bias assessment; reviewed data, results, and analyses; wrote, edited, and formatted monograph; provided database and HAWC support; supported data visualizations
  Pamela A. Hartman, M.E.M.