# References

Adedara IA, Abolaji AO, Idris UF, Olabiyi BF, Onibiyo EM, Ojuade TD, Farombi EO. 2017 a. Neuroprotective influence of taurine on fluoride-induced biochemical and behavioral deficits in rats. Chem Biol Interact. 261:1–10. 10.1016/j.cbi.2016.11.011 27840156
Adedara IA, Olabiyi BF, Ojuade TD, Idris UF, Onibiyo EM, Farombi EO. 2017 b. Taurine reverses sodium fluoride-mediated increase in inflammation, caspase-3 activity, and oxidative damage along the brain-pituitary-gonadal axis in male rats. Can J Physiol Pharmacol. 95(9):1019–1029. 10.1139/cjpp-2016-0641 28654759
Ahmad MS, Sarker MNI, Ahmad MN, Ali M, Sadiq, Abbas M. 2022. Does high fluoride intake cause low IQ? A case of Islamic religious schools (madrassas) in rural and urban areas of Sindh, Pakistan. Fluoride. 55(1):49–62.
Akinrinade ID, Memudu AE, Ogundele OM. 2015 a. Fluoride and aluminium disturb neuronal morphology, transport functions, cholinesterase, lysosomal and cell cycle activities. Pathophysiology. 22(2):105–115. 10.1016/j.pathophys.2015.03.001 25863844
Akinrinade ID, Memudu AE, Ogundele OM, Ajetunmobi OI. 2015 b. Interplay of glia activation and oxidative stress formation in fluoride and aluminium exposure. Pathophysiology. 22(1):39–48. 10.1016/j.pathophys.2014.12.001 25577494
An JA, Mei SZ, Liu AP, Fu Y, Wang CF. 1992. [Effect of high level of fluoride on children’s intelligence]. Chin J Control Endem Dis. 7(2):93–94.
Arbuckle TE, Fraser WD, Fisher M, Davis K, Liang CL, Lupien N, Bastien S, Velez MP, von Dadelszen P, Hemmings DG, et al. 2013. Cohort profile: The maternal-infant research on environmental chemicals research platform. Paediatr Perinat Epidemiol. 27(4):415–425. 10.1111/ppe.12061 23772943
Arroyave WD, Mehta SS, Guha N, Schwingl P, Taylor KW, Glenn B, Radke EG, Vilahur N, Carreón T, Nachman RM, et al. 2021. Challenges and recommendations on the conduct of systematic reviews of observational epidemiologic studies in environmental and occupational health. J Expo Sci Environ Epidemiol. 31(1):21–30. 10.1038/s41370-020-0228-0 32415298
Baba NA, Raina R, Verma PK, Sultana M. 2014. Alterations in plasma and tissue acetylcholinesterase activity following repeated oral exposure of chlorpyrifos alone and in conjunction with fluoride in Wistar rats. Proc Natl Acad Sci, India, Sect B Biol Sci. 84:969–972. 10.1007/s40011-013-0286-3
Banala RR, Nagapuri KK, Mohd KP, Reddy MM, Karnati PR. 2018. Carica Papaya leaf extract as a neuroprotective agent against behavioral and neurotransmitter changes in brain of the rat treated with sodium fluoride in pre- and post-natal periods. Pharmacogn Mag. 14(55) Suppl 1:S123–S131. 10.4103/pm.pm_378_17
Barberio AM, Hosein FS, Quiñonez C, McLaren L. 2017 a. Fluoride exposure and indicators of thyroid functioning in the Canadian population: Implications for community water fluoridation. J Epidemiol Community Health. 71(10):1019–1025. 10.1136/jech-2017-209129 28839078
Barberio AM, Quiñonez C, Hosein FS, McLaren L. 2017 b. Fluoride exposure and reported learning disability diagnosis among Canadian children: Implications for community water fluoridation. Can J Public Health. 108(3):e229–e239. 10.17269/CJPH.108.5951 28910243
Bartos M, Gumilar F, Gallegos CE, Bras C, Dominguez S, Mónaco N, Esandi MDC, Bouzat C, Cancela LM, Minetti A. 2018. Alterations in the memory of rat offspring exposed to low levels of fluoride during gestation and lactation: Involvement of the alpha7 nicotinic receptor and oxidative stress. Reprod Toxicol. 81:108–114. 10.1016/j.reprotox.2018.07.078 30009953
Bashash M, Marchand M, Hu H, Till C, Martinez-Mier EA, Sanchez BN, Basu N, Peterson KE, Green R, Schnaas L, et al. 2018. Prenatal fluoride exposure and attention deficit hyperactivity disorder (ADHD) symptoms in children at 6–12 years of age in Mexico City. Environ Int. 121(Pt 1):658–666. 10.1016/j.envint.2018.09.017 30316181
Bashash M, Thomas D, Hu H, Martinez-Mier EA, Sanchez BN, Basu N, Peterson KE, Ettinger AS, Wright R, Zhang Z, et al. 2017. Prenatal fluoride exposure and cognitive outcomes in children at 4 and 6-12 years of age in Mexico. Environ Health Perspect. 125(9):097017. 10.1289/EHP655 28937959
Bhatnagar M, Rao P, Sushma J, Bhatnagar R. 2002. Neurotoxicity of fluoride: Neurodegeneration in hippocampus of female mice. Indian J Exp Biol. 40(5):546–554. 12622200
Bhatnagar M, Sukhwal P, Suhalka P, Jain A, Joshi C, Sharma D. 2011. Effects of fluoride in drinking water on NADPH-diaphorase neurons in the forebrain of mice: A possible mechanism of fluoride neurotoxicity. Fluoride. 44(4):195–209.
Broadbent JM, Thomson WM, Moffitt TE, Poulton R. 2015. Community water fluoridation and intelligence: Broadbent et al. respond. Am J Public Health. 105(4):e3–e4. 10.2105/AJPH.2015.302647 25764384
California Office of Environmental Health Hazard Assessment (OEHHA). 2011. Meeting synopsis and slide presentations: Carcinogen Identification Committee meeting held on October 12, 2011. Sacramento, CA: California Office of Environmental Health Hazard Assessment. [Accessed: August 19, 2019]. https://oehha.ca.gov/prop65/public_meetings/cic101211synop.html
Cantoral A, Téllez-Rojo MM, Malin AJ, Schnaas L, Osorio-Valencia E, Mercado A, Martínez-Mier EA, Wright RO, Till C. 2021. Dietary fluoride intake during pregnancy and neurodevelopment in toddlers: A prospective study in the progress cohort. Neurotoxicology. 87:86–93. 10.1016/j.neuro.2021.08.015 34478773
Caruana EJ, Roman M, Hernández-Sánchez J, Solli P. 2015. Longitudinal studies. J Thorac Dis. 7(11):E537–E540. 10.3978/j.issn.2072-1439.2015.10.63 26716051
CDC Division of Oral Health. 2020. Personal communication. September 3, 2020.
Centers for Disease Control and Prevention (CDC). 2013. Community water fluoridation: Fluoridation statistics: 2012. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention. [Accessed: August 19, 2019]. https://web.archive.org/web/20190705104746/https://www.cdc.gov/fluoridation/statistics/2012stats.htm
Centers for Disease Control and Prevention (CDC). 2015. Community water fluoridation FAQs: Infant formula. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention. [Accessed: September 22, 2021]. https://web.archive.org/web/20210808212314/https:/www.cdc.gov/fluoridation/faqs/infant-formula.html
Chen Y. 2012. Organophosphate-induced brain damage: Mechanisms, neuropsychiatric and neurological consequences, and potential therapeutic strategies. Neurotoxicology. 33(3):391–400. 10.1016/j.neuro.2012.03.011 22498093
Chen YX, Han FL, Zhou ZL, Zhang HQ, Jiao XS, Zhang SC, Huang MC, Chang TQ, Dong YF. 1991. [Research on the intellectual development of children in high fluoride areas]. Chin J Control Endem Dis. 6 Suppl:99–100.
Chen YX, Han FL, Zhou ZL, Zhang HQ, Jiao XS, Zhang SC, Huang MC, Chang TQ, Dong YF. 2008. Research on the intellectual development of children in high fluoride areas. Fluoride. 41(2):120–124.
Chinoy NJ, Narayana MV. 1992. Studies on fluorosis in Mehsana District of North Gujarat. Proc Zool Soc Calcutta. 45(2):157–161.
Choi AL, Sun G, Zhang Y, Grandjean P. 2012. Developmental fluoride neurotoxicity: A systematic review and meta-analysis. Environ Health Perspect. 120(10):1362–1368. 10.1289/ehp.1104912 22820538
Choi AL, Zhang Y, Sun G, Bellinger DC, Wang K, Yang XJ, Li JS, Zheng Q, Fu Y, Grandjean P. 2015. Association of lifetime exposure to fluoride and cognitive functions in Chinese children: A pilot study. Neurotoxicol Teratol. 47:96–101. 10.1016/j.ntt.2014.11.001 25446012
Chouhan S, Flora SJS. 2008. Effects of fluoride on the tissue oxidative stress and apoptosis in rats: Biochemical assays supported by IR spectroscopy data. Toxicology. 254(1-2):61–67. 10.1016/j.tox.2008.09.008 18845224
Chouhan S, Lomash V, Flora SJS. 2010. Fluoride-induced changes in haem biosynthesis pathway, neurological variables and tissue histopathology of rats. J Appl Toxicol. 30(1):63–73. 10.1002/jat.1474 19743388
Cui Y, Yu J, Zhang B, Guo B, Gao T, Liu H. 2020. The relationships between thyroid-stimulating hormone and/or dopamine levels in peripheral blood and IQ in children with different urinary iodine concentrations. Neurosci Lett. 729:134981. 10.1016/j.neulet.2020.134981 32344109
Cui Y, Zhang B, Ma J, Wang Y, Zhao L, Hou C, Yu J, Zhao Y, Zhang Z, Nie J, et al. 2018. Dopamine receptor D2 gene polymorphism, urine fluoride, and intelligence impairment of children in China: A school-based cross-sectional study. Ecotoxicol Environ Saf. 165:270–277. 10.1016/j.ecoenv.2018.09.018 30205328
Dewey D, England-Mason G, Ntanda H, Deane AJ, Jain M, Barnieh N, Giesbrecht GF, Letourneau N, APrON Study Team. 2023. Fluoride exposure during pregnancy from a community water supply is associated with executive function in preschool children: A prospective ecological cohort study. Sci Total Environ. 891:164322. 10.1016/j.scitotenv.2023.164322 37236475
Ding Y, Gao Y, Sun H, Han H, Wang W, Ji X, Liu X, Sun D. 2011. The relationships between low levels of urine fluoride on children’s intelligence, dental fluorosis in endemic fluorosis areas in Hulunbuir, Inner Mongolia, China. J Hazard Mater. 186(2-3):1942–1946. 10.1016/j.jhazmat.2010.12.097 21237562
DTT Meta-analysis, Taylor KW, Eftim SE, Sibrizzi CA, Blain RB, Magnuson K, Hartman PA, Rooney AA, Bucher JR. 2024. Fluoride exposure and children’s intelligence: A systematic review and meta-analysis. In Press.
Du L, Wan C, Cao X, Liu J. 1992. [The effect of fluorine on the developing human brain]. Chin J Pathol. 21(4):218–220. 1473206
Du L, Wan C, Cao X, Liu J. 2008. The effect of fluorine on the developing human brain. Fluoride. 41(4):327–330.
Duan J, Zhao M, Wang L, Fang D, Wang Y, Wang W. 1995. A comparative analysis of the results of multiple tests in patients with chronic industrial fluorosis. Guizhou Med J. 18(3):179–180.
Duan Q, Jiao J, Chen X, Wang X. 2018. Association between water fluoride and the level of children’s intelligence: A dose-response meta-analysis. Public Health. 154:87–97. 10.1016/j.puhe.2017.08.013 29220711
Farmus L, Till C, Green R, Hornung R, Martinez Mier EA, Ayotte P, Muckle G, Lanphear BP, Flora DB. 2021. Critical windows of fluoride neurotoxicity in Canadian children. Environ Res. 200:111315. 10.1016/j.envres.2021.111315 34051202
Feng Z, An N, Yu F, Ma J, Li N, Du Y, Guo M, Xu K, Hou X, Li Z, et al. 2022. Do methylenetetrahydrofolate dehydrogenase, cyclohydrolase, and formyltetrahydrofolate synthetase 1 polymorphisms modify changes in intelligence of school-age children in areas of endemic fluorosis? Chin Med J (Engl). 135(15):1846–1854. 10.1097/CM9.0000000000002062 35838408
Gais S, Schönauer M. 2017. Untangling a cholinergic pathway from wakefulness to memory. Neuron. 94(4):696–698. 10.1016/j.neuron.2017.05.010 28521121
Gao Q, Liu YJ, Guan ZZ. 2009. Decreased learning and memory ability in rats with fluorosis: Increased oxidative stress and reduced cholinesterase activity in the brain. Fluoride. 42(4):277–285.
Gao Q, Liu YJ, Wu CX, Long YG, Guan ZZ. 2008 a. [Effects of fluoride on learning and memory and cholinesterase activity in rat brains]. Chin J Endemiol. 27(2):128–130. 10.3760/cma.j.issn.1000-4955.2008.02.004
Gao Q, Liu YJ, Wu CX, Long YG, Guan ZZ. 2008 b. [Level of oxidative stress in rat brains and learning and memory function of rats with chronic fluorosis]. Chin J Endemiol. 27(4):371–373. 10.3760/cma.j.issn.1000-4955.2008.04.006
Garman RH, Li AA, Kaufmann W, Auer RN, Bolon B. 2016. Recommended methods for brain processing and quantitative analysis in rodent developmental neurotoxicity studies. Toxicol Pathol. 44(1):14–42. 10.1177/0192623315596858 26296631
Goodman CV, Bashash M, Green R, Song P, Peterson KE, Schnaas L, Mercado-García A, Martínez-Medina S, Hernández-Avila M, Martinez-Mier A, et al. 2022 a. Domain-specific effects of prenatal fluoride exposure on child IQ at 4, 5, and 6–12 years in the ELEMENT cohort. Environ Res. 211:112993. 10.1016/j.envres.2022.112993 35276192
Goodman CV, Hall M, Green R, Chevrier J, Ayotte P, Martinez-Mier EA, McGuckin T, Krzeczkowski J, Flora D, Hornung R, et al. 2022 b. Iodine status modifies the association between fluoride exposure in pregnancy and preschool boys’ intelligence. Nutrients. 14(14):2920. 10.3390/nu14142920 35889877
Grandjean P, Meddis A, Nielsen F, Beck IH, Bilenberg N, Goodman CV, Hu H, Till C, Budtz-Jørgensen E. 2023. Dose dependence of prenatal fluoride exposure associations with cognitive performance at school age in three prospective studies. Eur J Public Health. 34(1):143–149. 10.1093/eurpub/ckad170 37798092
Green R, Lanphear B, Hornung R, Flora D, Martinez-Mier EA, Neufeld R, Ayotte P, Muckle G, Till C. 2019. Association between maternal fluoride exposure during pregnancy and IQ scores in offspring in Canada. JAMA Pediatr. 173(10):940–948. 10.1001/jamapediatrics.2019.1729 31424532
Green R, Rubenstein J, Popoli R, Capulong R, Till C. 2020. Sex-specific neurotoxic effects of early-life exposure to fluoride: A review of the epidemiologic and animal literature. Curr Epidemiol Rep. 7(4):263–273. 10.1007/s40471-020-00246-1 33816056
Güner Ş, Uyar-Bozkurt S, Haznedaroğlu E, Menteş A. 2016. Dental fluorosis and catalase immunoreactivity of the brain tissues in rats exposed to high fluoride pre- and postnatally. Biol Trace Elem Res. 174(1):150–157. 10.1007/s12011-016-0695-2 27052310
Guo XC, Wang RY, Cheng CF, Wei WS, Tang LM, Wang QS, Tang DX, Liu GW, He GD, Li SL. 1991. [A preliminary investigation of the IQs of 7-13 year-old children from an area with coal burning-related fluoride poisoning]. Chin J Endemiol. 10(2):98–100.
Guo XC, Wang RY, Cheng CF, Wei WS, Tang LM, Wang QS, Tang DX, Liu GW, He GD, Li SL. 2008 a. A preliminary investigation of the IQs of 7-13 year-old children from an area with coal burning-related fluoride poisoning. Fluoride. 41(2):125–128.
Guo ZY, He YH, Zhu QX. 2001. [Research on the neurobehavioral function of workers occupationally exposed to fluoride]. Ind Health Occup Dis. 27(6):346–348.
Guo ZY, He YH, Zhu QX. 2008 b. Research on the neurobehavioral function of workers occupationally exposed to fluoride. Fluoride. 41(2):152–155.
Guyatt G, Oxman AD, Akl EA, Kunz R, Vist G, Brozek J, Norris S, Falck-Ytter Y, Glasziou P, deBeer H, et al. 2011. GRADE guidelines: 1. Introduction-GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. 64(4):383–394. 10.1016/j.jclinepi.2010.04.026 21195583
Haschek WM, Rousseaux CG. 1991. Handbook of toxicologic pathology. San Diego, CA: Academic Press.
Health Canada. 2015. Third report on human biomonitoring of environmental chemicals in Canada: Results of the Canadian Health Measures Survey Cycle 3 (2012–2013). Ottawa, Ontario: Health Canada. https://www.canada.ca/content/dam/hc-sc/migration/hc-sc/ewh-semt/alt_formats/pdf/pubs/contaminants/chms-ecms-cycle3/chms-ecms-cycle3-eng.pdf
Hefferon R, Goin DE, Sarnat JA, Nigra AE. 2024. Regional and racial/ethnic inequalities in public drinking water fluoride concentrations across the US. J Expo Sci Environ Epidemiol. 34(1):68–76. 10.1038/s41370-023-00570-w 37391608
Higgins JPT, Green S. 2011. Cochrane handbook for systematic reviews of interventions. Hoboken, NJ: John Wiley & Sons.
Higgins JPT, Morgan RL, Rooney AA, Taylor KW, Thayer KA, Silva RA, Lemeris C, Akl EA, Bateson TF, Berkman ND, et al. 2024. A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environ Int. 186:108602. 10.1016/j.envint.2024.108602 38555664
Hosur MB, Puranik RS, Vanaki S, Puranik SR. 2012. Study of thyroid hormones free triiodothyronine (FT3), free thyroxine (FT4) and thyroid stimulating hormone (TSH) in subjects with dental fluorosis. Eur J Dent. 6(2):184–190. 10.1055/s-0039-1698949 22509122
Howard BE, Phillips J, Tandon A, Maharana A, Elmore R, Mav D, Sedykh A, Thayer K, Merrick BA, Walker V, et al. 2020. SWIFT-Active Screener: Accelerated document screening through active learning and integrated recall estimation. Environ Int. 138:105623. 10.1016/j.envint.2020.105623 32203803
Huang Q, Liao C, Ge F, Ao J, Liu T. 2022. Acetylcholine bidirectionally regulates learning and memory. J Neurorestoratology. 10(2):100002. 10.1016/j.jnrt.2022.100002
Ibarluzea J, Gallastegi M, Santa-Marina L, Jiménez Zabala A, Arranz E, Molinuevo A, Lopez-Espinosa MJ, Ballester F, Villanueva CM, Riano I, et al. 2021. Prenatal exposure to fluoride and neuropsychological development in early childhood: 1-to 4 years old children. Environ Res. 207:112181. 10.1016/j.envres.2021.112181 34627799
International Programme on Chemical Safety (IPCS). 2002. Fluorides. Geneva, Switzerland: World Health Organization, International Programme on Chemical Safety. Environ Health Criteria 227. https://inchem.org/documents/ehc/ehc/ehc227.htm
Jacqmin H, Commenges D, Letenneur L, Barberger-Gateau P, Dartigues JF. 1994. Components of drinking water and risk of cognitive impairment in the elderly. Am J Epidemiol. 139(1):48–57. 10.1093/oxfordjournals.aje.a116934 8296774
Jia B, Zong L, Lee JY, Lei J, Zhu Y, Xie H, Clemens JL, Feller MC, Na Q, Dong J, et al. 2019. Maternal supplementation of low dose fluoride alleviates adverse perinatal outcomes following exposure to intrauterine inflammation. Sci Rep. 9(1):2575. 10.1038/s41598-018-38241-8 30796233
Jiang C, Zhang S, Liu H, Guan Z, Zeng Q, Zhang C, Lei R, Xia T, Wang Z, Yang L, et al. 2014. Low glucose utilization and neurodegenerative changes caused by sodium fluoride exposure in rat’s developmental brain. Neuromolecular Med. 16(1):94–105. 10.1007/s12017-013-8260-z 23982469
Jin T, Han T, Wei Y, Wu Y, Wang Z, Zhang H. 2016. Investigation on working memory level of children aged 8-12 years in coal-burning fluorosis area. Journal of Environment and Health. 33(5):409–411.
Johnston NR, Strobel SA. 2020. Principles of fluoride toxicity and the cellular response: A review. Arch Toxicol. 94(4):1051–1069. 10.1007/s00204-020-02687-5 32152649
Jones S, Burt BA, Petersen PE, Lennon MA. 2005. The effective use of fluorides in public health. Bull World Health Organ. 83(9):670–676. 16211158
Jüni P, Witschi A, Bloch R, Egger M. 1999. The hazards of scoring the quality of clinical trials for meta-analysis. JAMA. 282(11):1054–1060. 10.1001/jama.282.11.1054 10493204
Khan AM, Raina R, Dubey N, Verma PK. 2017. Effect of deltamethrin and fluoride co-exposure on the brain antioxidant status and cholinesterase activity in Wistar rats. Drug Chem Toxicol. 41(2):123–127. 10.1080/01480545.2017.1321009 28503953
Khandare AL, Gourineni SR, Validandi V. 2017. Dental fluorosis, nutritional status, kidney damage, and thyroid function along with bone metabolic indicators in school-going children living in fluoride-affected hilly areas of Doda District, Jammu and Kashmir, India. Environ Monit Assess. 189(11):579. 10.1007/s10661-017-6288-5 29063198
Khandare AL, Validandi V, Gourineni SR, Gopalan V, Nagalla B. 2018. Dose-dependent effect of fluoride on clinical and subclinical indices of fluorosis in school going children and its mitigation by supply of safe drinking water for 5 years: An Indian study. Environ Monit Assess. 190(3):110. 10.1007/s10661-018-6501-1 29396763
Kheradpisheh Z, Mahvi AH, Mirzaei M, Mokhtari M, Azizi R, Fallahzadeh H, Ehrampoush MH. 2018 a. Correlation between drinking water fluoride and TSH hormone by ANNs and ANFIS. J Environ Health Sci Eng. 16(1):11–18. 10.1007/s40201-018-0290-x 30258638
Kheradpisheh Z, Mirzaei M, Mahvi AH, Mokhtari M, Azizi R, Fallahzadeh H, Ehrampoush MH. 2018 b. Impact of drinking water fluoride on human thyroid hormones: A case-control study. Sci Rep. 8(1):2674. 10.1038/s41598-018-20696-4 29422493
Kumar JV, Moss ME, Liu H, Fisher-Owens S. 2023. Association between low fluoride exposure and children’s intelligence: A meta-analysis relevant to community water fluoridation. Public Health. 219:73–84. 10.1016/j.puhe.2023.03.011 37120936
Kumar V, Chahar P, Kajjari S, Rahman F, Bansal DK, Kapadia JM. 2018. Fluoride, thyroid hormone derangements and its correlation with tooth eruption pattern among the pediatric population from endemic and non-endemic fluorosis areas. J Contemp Dent Pract. 19(12):1512–1516. 30713182
Li D, Zhao Q, Xie L, Wang C, Tian Z, Tang H, Xia T, Wang A. 2023. Fluoride impairs mitochondrial translation by targeting miR-221-3p/c-Fos/RMND1 axis contributing to neurodevelopment defects. Sci Total Environ. 869:161738. 10.1016/j.scitotenv.2023.161738 36690096
Li F, Chen X, Huang R, Xie Y. 2009. The impact of endemic fluorosis caused by the burning of coal on the development of intelligence in children. Journal of Environment and Health. 26(4):838–840.
Li J, Yao L, Shao QL, Wu CY. 2004. [Effects of high fluoride level on neonatal neurobehavioral development]. Chin J Endemiol. 23(5):463–465. 10.3760/cma.j.issn.1000-4955.2004.05.023
Li J, Yao L, Shao QL, Wu CY. 2008 a. Effects of high fluoride level on neonatal neurobehavioral development. Fluoride. 41(2):165–170.
Li M, Gao Y, Cui J, Li Y, Li B, Liu Y, Sun J, Liu X, Liu H, Zhao L, et al. 2016. Cognitive impairment and risk factors in elderly people living in fluorosis areas in China. Biol Trace Elem Res. 172(1):53–60. 10.1007/s12011-015-0568-0 26606914
Li X, Hou G, Yu B, Yuan C, Liu Y, Zhang L. 2010. [Investigation and analysis of children’s IQ and dental fluorosis in high fluoride area]. Chin J Pest Control. 26(3):230–231.
Li Y, Jing X, Chen D, Lin L, Wang Z. 2003. [Effects of endemic fluoride poisoning on the intellectual development of children in Baotou]. Chin J Public Health Manag. 19(4):337–338.
Li Y, Jing X, Chen D, Lin L, Wang Z. 2008 c. Effects of endemic fluoride poisoning on the intellectual development of children in Baotou. Fluoride. 41(2):161–164.
Li Y, Li X, Wei S. 1994. [Effects of high fluoride intake on child mental work capacity: Preliminary investigation into the mechanisms involved]. J West Chin University Med Sci. 25(2):188–191.
Li Y, Li X, Wei S. 2008 b. Effects of high fluoride intake on child mental work capacity: Preliminary investigation into the mechanisms involved. Fluoride. 41(4):331–335.
Liang C, Ji R, Cao J, Jiang Y, Yu B, Ma F, Wu Y, Ying B, Zhang Y, Sun S, et al. 2003. [Study on the relationship between drinking water trace elements and cognitive ability of the elderly]. J Hyg Res. 32(5):436–440.
Lin FF, Ai HT, Zhao HX, Lin J, Jhiang JY, et al. 1991. [High fluoride and low iodine environment and subclinical cretinism in Xinjiang]. Endemic Dis Bull. 6(2):62–67.
Lin YY, Hsu WY, Yen CE, Hu SW. 2023. Association of dental fluorosis and urinary fluoride with intelligence among schoolchildren. Children (Basel). 10(6):987. 10.3390/children10060987 37371219
Liu YJ, Gao Q, Wu CX, Guan ZZ. 2010. Alterations of nAChRs and ERK1/2 in the brains of rats with chronic fluorosis and their connections with the decreased capacity of learning and memory. Toxicol Lett. 192(3):324–329. 10.1016/j.toxlet.2009.11.002 19900517
Lou DD, Guan ZZ, Liu YJ, Liu YF, Zhang KL, Pan JG, Pei JJ. 2013. The influence of chronic fluorosis on mitochondrial dynamics morphology and distribution in cortical neurons of the rat brain. Arch Toxicol. 87(3):449–457. 10.1007/s00204-012-0942-z 23007560
Lu F, Zhang Y, Trivedi A, Jiang X, Chandra D, Zheng J, Nakano Y, Uyghurturk DA, Jalai R, Onur SG, et al. 2019. Fluoride related changes in behavioral outcomes may relate to increased serotonin. Physiol Behav. 206:76–83. 10.1016/j.physbeh.2019.02.017 30904570
Ma Q, Huang H, Sun L, Zhou T, Zhu J, Cheng X, Duan L, Li Z, Cui L, Ba Y. 2017. Gene-environment interaction: Does fluoride influence the reproductive hormones in male farmers modified by ERα gene polymorphisms? Chemosphere. 188:525–531. 10.1016/j.chemosphere.2017.08.166 28910727
Malin AJ, Riddell J, McCague H, Till C. 2018. Fluoride exposure and thyroid function among adults living in Canada: Effect modification by iodine status. Environ Int. 121(Pt 1):667–674. 10.1016/j.envint.2018.09.026 30316182
Malin AJ, Till C. 2015. Exposure to fluoridated water and attention deficit hyperactivity disorder prevalence among children and adolescents in the United States: An ecological association. Environ Health. 14:17. 10.1186/s12940-015-0003-1 25890329
McDonell KE, van Wouwe NC, Harrison MB, Wylie SA, Claassen DO. 2018. Taq1A polymorphism and medication effects on inhibitory action control in Parkinson disease. Brain Behav. 8(7):e01008. 10.1002/brb3.1008 29856137
McPherson CA, Zhang G, Gilliam R, Brar SS, Wilson R, Brix A, Picut C, Harry GJ. 2018. An evaluation of neurotoxicity following fluoride exposure from gestational through adult ages in Long-Evans hooded rats. Neurotox Res. 34(4):781–798. 10.1007/s12640-018-9870-x 29404855
Mesram N, Nagapuri K, Banala RR, Nalagoni CR, Karnati PR. 2016. Quercetin treatment against NaF induced oxidative stress related neuronal and learning changes in developing rats. J King Saud Univ Sci. 29(2):221–229. 10.1016/j.jksus.2016.04.002
Michael M, Barot VV, Chinoy NJ. 1996. Investigations of soft tissue functions in fluorotic individuals of North Gujarat. Fluoride. 29(2):63–71.
Miller K, Howard BE, Phillips J, Shah M, Mav D, Thayer K, Shah R. 2016. SWIFT-Active Screener: Reducing literature screening effort through machine learning for systematic reviews. 24th Cochrane Colloquium, Seoul, South Korea, October 23-27, 2016.
Miranda GHN, Alvarenga MOP, Ferreira MKM, Puty B, Bittencourt LO, Fagundes NCF, Pessan JP, Buzalaf MAR, Lima RR. 2021. A systematic review and meta-analysis of the association between fluoride exposure and neurological disorders. Sci Rep. 11(1):22659. 10.1038/s41598-021-99688-w 34811523
Morgan L, Allred E, Tavares M, Bellinger D, Needleman H. 1998. Investigation of the possible associations between fluorosis, fluoride exposure, and childhood behavior problems. Pediatr Dent. 20(4):244–252. 9783294
Mustafa DE, Younis UM, Elhag SAA. 2018. The relationship between the fluoride levels in drinking water and the schooling performance of children in rural areas of Khartoum State, Sudan. Fluoride. 51(2):102–113.
Nageshwar M, Sudhakar K, Reddy KP. 2018. Quercetin ameliorates oxidative stress, neural damage of brain and behavioral impairment of rat with fluoride exposure. Int J Pharm Sci Res. 9(8):3247–3256. 10.13040/IJPSR.0975-8232.9(8).3247-56
National Academies of Sciences, Engineering, and Medicine (NASEM). 2020. Review of the draft NTP monograph: Systematic review of fluoride exposure and neurodevelopmental and cognitive health effects. Washington, DC: The National Academies Press. 10.17226/25715
National Academies of Sciences, Engineering, and Medicine (NASEM). 2021. Review of the revised NTP monograph on the systematic review of fluoride exposure and neurodevelopmental and cognitive health effects: A letter report. Washington, DC: The National Academies Press. 10.17226/26030
National Institute for Occupational Safety and Health (NIOSH). 1984. Fluoride in urine: Method 8308. In: NIOSH Manual of Analytical Methods. Volume 11. 3rd ed. Cincinnati, OH: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health.
National Research Council (NRC). 2006. Fluoride in drinking water: A scientific review of EPA’s standards. Washington, DC: The National Academies Press. 10.17226/11571
National Toxicology Program (NTP). 2016. NTP research report on systematic literature review on the effects of fluoride on learning and memory in animal studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. NTP Research Report 1. 10.22427/NTP-RR-1
National Toxicology Program (NTP). 2019. Health Assessment Workspace Collaborative (HAWC): Fluoride (2019). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program. [Accessed: 2019]. https://hawcproject.org/assessment/405/
National Toxicology Program (NTP). 2020. Revised draft NTP monograph on the systematic review of fluoride exposure and neurodevelopmental and cognitive health effects. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Institute of Environmental Health Sciences, Division of the National Toxicology Program, Office of Health Assessment and Translation. https://fluoridealert.org/wp-content/uploads/ntp.revised-monograph.9-16-2020.pdf
National Toxicology Program (NTP). 2024. Data and protocol for systematic review of fluoride exposure and neurodevelopmental and cognitive health effects. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program. 10.22427/NTP-DATA-MGRAPH-8
Niu Q, Chen J, Xia T, Li P, Zhou G, Xu C, Zhao Q, Dong L, Zhang S, Wang A. 2018. Excessive ER stress and the resulting autophagic flux dysfunction contribute to fluoride-induced neurotoxicity. Environ Pollut. 233:889–899. 10.1016/j.envpol.2017.09.015 29100748
Nkpaa KW, Onyeso GI. 2018. Rutin attenuates neurobehavioral deficits, oxidative stress, neuro-inflammation and apoptosis in fluoride treated rats. Neurosci Lett. 682:92–99. 10.1016/j.neulet.2018.06.023 29908257
Page MJ, McKenzie JE, Bossuyt PM, Boutron I, Hoffmann TC, Mulrow CD, Shamseer L, Tetzlaff JM, Akl EA, Brennan SE, et al. 2021. The PRISMA 2020 statement: An updated guideline for reporting systematic reviews. BMJ. 372:n71. 10.1136/bmj.n71 33782057
Peckham S, Lowery D, Spencer S. 2015. Are fluoride levels in drinking water associated with hypothyroidism prevalence in England? A large observational study of GP practice data and fluoride levels in drinking water. J Epidemiol Community Health. 69(7):619–624. 10.1136/jech-2014-204971 25714098
Podgorski J, Berg M. 2020. Global threat of arsenic in groundwater. Science. 368(6493):845–850. 10.1126/science.aba1510 32439786
Podgorski J, Berg M. 2022. Global analysis and prediction of fluoride in groundwater. Nat Commun. 13(1):4232. 10.1038/s41467-022-31940-x 35915064
Pratap SV, Singh CD, Sandeep T, Sandeep K, Vikas G, Mukesh T, Anurag T. 2013. A correlation between serum vitamin, acetylcholinesterase activity and IQ in children with excessive endemic fluoride exposure in Rajasthan, India. Int Res J Med Sci. 1(3):12–16.
Pulungan ZSA, Sofro ZM, Partadiredja G. 2016. Sodium fluoride does not affect the working memory and number of pyramidal cells in rat medial prefrontal cortex. Anat Sci Int. 93(1):128–138. 10.1007/s12565-016-0384-4 27990615
Reddy YP, Tiwari SK, Shaik AP, Alsaeed A, Sultana A, Reddy PK. 2014. Effect of sodium fluoride on neuroimmunological parameters, oxidative stress and antioxidative defenses. Toxicol Mech Methods. 24(1):31–36. 10.3109/15376516.2013.843224 24024668
Ren D, Li K, Liu D. 1989. [A study of the intellectual ability of 8-14 year-old children in high fluoride, low iodine areas]. Chin J Control Endem Dis. 4(4):251.
Ren D, Li K, Liu D. 2008. A study of the intellectual ability of 8-14 year-old children in high fluoride, low iodine areas. Fluoride. 41(4):319–320.
Riddell JK, Malin AJ, Flora D, McCague H, Till C. 2019. Association of water fluoride and urinary fluoride concentrations with attention deficit hyperactivity disorder in Canadian youth. Environ Int. 133(Pt B):105190. 10.1016/j.envint.2019.105190 31654913
Rocha-Amador D, Navarro M, Trejo-Acevedo A, Carrizales L, Pérez-Maldonado I, Díaz-Barriga F, Calderón J. 2009. Use of the Rey-Osterrieth Complex Figure Test for neurotoxicity evaluation of mixtures in children. Neurotoxicology. 30(6):1149–1154. 10.1016/j.neuro.2009.09.003 19770001
Rocha-Amador D, Navarro ME, Carrizales L, Morales R, Calderón J. 2007. Decreased intelligence in children and exposure to fluoride and arsenic in drinking water. Cad Saude Publica. 23 Suppl 4:S579–S587. 10.1590/S0102-311X2007001600018 18038039
Rooney AA, Boyles AL, Wolfe MS, Bucher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Rotton J, Tikofsky RS, Feldman HT. 1982. Behavioral effects of chemicals in drinking water. J Appl Psychol. 67(2):230–238. 10.1037/0021-9010.67.2.230 7085537
Russ TC, Killin LOJ, Hannah J, Batty GD, Deary IJ, Starr JM. 2019. Aluminium and fluoride in drinking water in relation to later dementia risk. Br J Psychiatry. 216(1):29–34. 10.1192/bjp.2018.287 30868981
Santa-Marina L, Jimenez-Zabala A, Molinuevo A, Lopez-Espinosa M, Villanueva C, Riano I, Ballester F, Sunyer J, Tardon A, Ibarluzea J. 2019. Fluorinated water consumption in pregnancy and neuropsychological development of children at 14 months and 4 years of age. Environ Epidemiol. 3:386–387. 10.1097/01.EE9.0000610304.33479.18
Savitz DA, Wellenius GA, Trikalinos TA. 2019. The problem with mechanistic risk of bias assessments in evidence synthesis of observational studies and a practical alternative: Assessing the impact of specific sources of potential bias. Am J Epidemiol. 188(9):1581–1585. 10.1093/aje/kwz131 31145434
Saxena S, Sahay A, Goel P. 2012. Effect of fluoride exposure on the intelligence of school children in Madhya Pradesh, India. J Neurosci Rural Pract. 3(2):144–149. 10.4103/0976-3147.98213 22865964
Scientific Committee on Health and Environmental Risks (SCHER). 2011. Critical review of any new evidence on the hazard profile, health effects, and human exposure to fluoride and the fluoridating agents of drinking water. Brussels, Belgium: European Commission, Directorate-General for Health and Consumers. https://ec.europa.eu/health/scientific_committees/environmental_risks/docs/scher_o_139.pdf
Sebastian ST, Sunitha S. 2015. A cross-sectional study to assess the intelligence quotient (IQ) of school going children aged 10-12 years in villages of Mysore District, India with different fluoride levels. J Indian Soc Pedod Prev Dent. 33(4):307–311. 10.4103/0970-4388.165682 26381633
Seraj B, Shahrabi M, Shadfar M, Ahmadi R, Fallahzadeh M, Eslamlu HF, Kharazifard MJ. 2012. Effect of high water fluoride concentration on the intellectual development of children in Makoo/Iran. J Dent (Tehran). 9(3):221–229. 23119131
Shan KR, Qi XL, Long YG, Nordberg A, Guan ZZ. 2004. Decreased nicotinic receptors in PC12 cells and rat brains influenced by fluoride toxicity—A mechanism relating to a damage at the level in post-transcription of the receptor genes. Toxicology. 200(2-3):169–177. 10.1016/j.tox.2004.03.013 15212813
Shannon FT, Fergusson DM, Horwood LJ. 1986. Exposure to fluoridated public water supplies and child health and behaviour. N Z Med J. 99(803):416–418. 3461356
Shao Q. 2003. [Study of cognitive function impairment caused by chronic fluorosis]. Chin J Endemiol. 22(4):336–338. 10.3760/cma.j.issn.1000-4955.2003.04.016
Sharma JD, Sohu D, Jain P. 2009. Prevalence of neurological manifestations in a human population exposed to fluoride in drinking water. Fluoride. 42(2):127–132.
Singh N, Verma KG, Verma P, Sidhu GK, Sachdeva S. 2014. A comparative study of fluoride ingestion levels, serum thyroid hormone & TSH level derangements, dental fluorosis status among school children from endemic and non-endemic fluorosis areas. Springerplus. 3:7. 10.1186/2193-1801-3-7 24455464
Singla VI, Sutton PM, Woodruff TJ. 2019. The Environmental Protection Agency Toxic Substances Control Act systematic review method may curtail science used to inform policies, with profound implications for public health. Am J Public Health. 109(7):982–984. 10.2105/AJPH.2019.305068 31166745
Soto-Barreras U, Escalante-Villalobos KY, Holguín-Loya B, Perez-Aguirre B, Nevárez-Rascón A, Martínez-Martínez RE, Loyola-Rodriguez JP. 2019. Effect of fluoride in drinking water on dental caries and IQ in children. Fluoride. 52(3 Pt 3):474–482.
Stang A. 2010. Critical evaluation of the Newcastle-Ottawa scale for the assessment of the quality of nonrandomized studies in meta-analyses. Eur J Epidemiol. 25(9):603–605. 10.1007/s10654-010-9491-z 20652370
Steenland K, Schubauer-Berigan MK, Vermeulen R, Lunn RM, Straif K, Zahm S, Stewart P, Arroyave WD, Mehta SS, Pearce N. 2020. Risk of bias assessments and evidence syntheses for observational epidemiologic studies of environmental and occupational exposures: Strengths and limitations. Environ Health Perspect. 128(9):095002. 10.1289/EHP6980 32924579
Sterne JAC, Hernán MA, McAleenan A, Reeves BC, Higgins JPT. 2023. Chapter 25: Assessing risk of bias in a non-randomized study. In: Higgins JPT, Thomas J, Chandler J, Cumpston M, Li T, Page MJ, Welch VA, editors. Cochrane Handbook for Systematic Reviews of Interventions version 6.4 (updated August 2023). London, UK: The Cochrane Collaboration. https://training.cochrane.org/handbook
Still CN, Kelley P. 1980. On the incidence of primary degenerative dementia vs. water fluoride content in South Carolina. Neurotoxicology. 1(4):125–131.
Sudhakar K, Reddy KP. 2018. Protective effects of Abelmoschus moschatus seed extract on neurotransmitter system of developing brain of Wistar rats with gestational and post-natal exposure of sodium fluoride. Int J Green Pharm. 12(1) Suppl:S131–S139. 10.22377/ijgp.v12i01.1609
Sudhir KM, Chandu GN, Prashant GM, Subba Reddy VV. 2009. Effect of fluoride exposure on intelligence quotient (IQ) among 13-15 year old school children of known endemic area of fluorosis, Nalgonda District, Andhra Pradesh. J Indian Assoc Public Health Dent.(13):88–94.
Sun MM, Li SK, Wang YF, Li FS. 1991. [Measurement of intelligence by drawing test among the children in the endemic area of Al-F combined toxicosis]. J Guiyang Med Coll. 16(3):204–206.
Sun ZR, Liu FZ, Wu LN, Lu Y, Yu DK. 2000. [Effects of high fluoride drinking water on the cerebral function of mice]. Chin J Endemiol. 19(4):262–263. 10.3760/cma.j.issn.1000-4955.2000.04.009
Sun ZR, Liu FZ, Wu LN, Lu Y, Yu DK. 2008. Effects of high fluoride drinking water on the cerebral function of mice. Fluoride. 41(2):148–151.
Susheela AK, Bhatnagar M, Vig K, Mondal NK. 2005. Excess fluoride ingestion and thyroid hormone derangements in children living in Delhi, India. Fluoride. 38(2):98–108.
Tang QQ, Du J, Ma HH, Jiang SJ, Zhou XJ. 2008. Fluoride and children’s intelligence: A meta-analysis. Biol Trace Elem Res. 126(1-3):115–120. 10.1007/s12011-008-8204-x 18695947
Till C, Green R, Flora D, Hornung R, Martinez-Mier EA, Blazer M, Farmus L, Ayotte P, Muckle G, Lanphear B. 2020. Fluoride exposure from infant formula and child IQ in a Canadian birth cohort. Environ Int. 134:105315. 10.1016/j.envint.2019.105315 31743803
Till C, Green R, Grundy JG, Hornung R, Neufeld R, Martinez-Mier EA, Ayotte P, Muckle G, Lanphear B. 2018. Community water fluoridation and urinary fluoride concentrations in a national sample of pregnant women in Canada. Environ Health Perspect. 126(10):107001. 10.1289/EHP3546 30392399
Trivedi MH, Sangai NP, Patel RS, Payak M, Vyas SJ. 2012. Assessment of groundwater quality with special reference to fluoride and its impact on IQ of schoolchildren in six villages of the Mundra Region, Kachchh, Gujurat, India. Fluoride. 45(4):377–383.
Trivedi MH, Verma RJ, Chinoy NJ, Patel RS, Sathawara NG. 2007. Effect of high fluoride water on intelligence of school children in India. Fluoride. 40(3):178–183.
Tsunoda M, Aizawa Y, Nakano K, Liu Y, Horiuchi T, Itai K, Tsunoda H. 2005. Changes in fluoride levels in the liver, kidney, and brain and in neurotransmitters of mice after subacute administration of fluoride. Fluoride. 38(4):284–292.
U.S. Department of Health and Human Services Federal Panel on Community Water Fluoridation (USDHHS). 2015. U.S. Public Health Service recommendation for fluoride concentration in drinking water for the prevention of dental caries. Public Health Rep. 130(4):318–331. 10.1177/003335491513000408 26346489
U.S. Environmental Protection Agency (USEPA). 2010. Fluoride: Exposure and relative source contribution analysis. Washington, DC: U.S. Environmental Protection Agency. EPA Report No. 820-R-10-015. https://www.epa.gov/dwstandardsregulations/fluoride-risk-assessment-and-relative-source-contribution
U.S. Geological Survey (USGS). 2020. Fluoride in groundwater: Too much or too little of a good thing? Lakewood, CO: U.S. Geological Survey, Water Resources Mission Area, Colorado Water Science Center. https://www.usgs.gov/news/comprehensive-assessment-fluoride-groundwater
Valdez Jiménez L, López Guzmán OD, Cervantes Flores M, Costilla-Salazar R, Calderón Hernández J, Alcaraz Contreras Y, Rocha-Amador DO. 2017. In utero exposure to fluoride and cognitive development delay in infants. Neurotoxicology. 59:65–70. 10.1016/j.neuro.2016.12.011 28077305
Veneri F, Vinceti M, Generali L, Giannone ME, Mazzoleni E, Birnbaum LS, Consolo U, Filippini T. 2023. Fluoride exposure and cognitive neurodevelopment: Systematic review and dose-response meta-analysis. Environ Res. 221:115239. 10.1016/j.envres.2023.115239 36639015
Villa A, Anabalon M, Zohouri V, Maguire A, Franco AM, Rugg-Gunn A. 2010. Relationships between fluoride intake, urinary fluoride excretion and fluoride retention in children and adults: An analysis of available data. Caries Res. 44(1):60–68. 10.1159/000279325 20130402
Walker VR, Lemeris CR, Magnuson K, Sibrizzi CA, Shipkowski KA, Taylor KW, Rooney AA. 2024. I-REFF diagrams: Enhancing transparency in systematic review through interactive reference flow diagrams. Syst Rev. 13(1):33. 10.1186/s13643-023-02420-0 38233900
Wang A, Duan L, Huang H, Ma J, Zhang Y, Ma Q, Guo Y, Li Z, Cheng X, Zhu J, et al. 2020 a. Association between fluoride exposure and behavioural outcomes of school-age children: A pilot study in China. Int J Environ Health Res. 32(1):232–241. 10.1080/09603123.2020.1747601 32281876
Wang G, Gao M, Zhang M, Yang M, Xiang Q. 2012. Correlation between total fluoride intake and children's IQ. J Southeast Univ Med Ed. 31(6):743–746.
Wang M, Liu L, Li H, Li Y, Liu H, Hou C, Zeng Q, Li P, Zhao Q, Dong L, et al. 2020 b. Thyroid function, intelligence, and low-moderate fluoride exposure among Chinese school-age children. Environ Int. 134:105229. 10.1016/j.envint.2019.105229 31698198
Wang S, Zhao Q, Li G, Wang M, Liu H, Yu X, Chen J, Li P, Dong L, Zhou G, et al. 2021 c. The cholinergic system, intelligence, and dental fluorosis in school-aged children with low-to-moderate fluoride exposure. Ecotoxicol Environ Saf. 228:112959. 10.1016/j.ecoenv.2021.112959 34808511
Wang X, Wang L, Hu P, Guo X, Luo X. 2001. [Effects of high iodine and high fluorine on children’s intelligence and thyroid function]. Chin J Endemiol. 20(4):288–290. 10.3760/cma.j.issn.1000-4955.2001.04.017
Watanabe M, Kono K, Orita Y, Dote T, Usuda K, Takahashi Y, Yoshida Y. 1995. Influence of dietary fluoride intake on urinary fluoride concentration and evaluation of corrected levels in spot urine. Fluoride. 28(2):61–70.
Waugh DT. 2019. Fluoride exposure induces inhibition of sodium/iodide symporter (NIS) contributing to impaired iodine absorption and iodine deficiency: Molecular mechanisms of inhibition and implications for public health. Int J Environ Res Public Health. 16(6):1086. 10.3390/ijerph16061086 30917615
World Health Organization (WHO). 2008. Guidelines for drinking-water quality: Incorporating the first and second addenda, volume 1: Recommendations. 3rd ed. Geneva, Switzerland: World Health Organization. https://apps.who.int/iris/bitstream/handle/10665/204411/9789241547611_eng.pdf?sequence=1&isAllowed=y
World Health Organization (WHO). 2017. Guidelines for drinking-water quality: Fourth edition incorporating the first addendum. Geneva, Switzerland: World Health Organization. https://apps.who.int/iris/handle/10665/254637
Xia Y, Xu Y, Shi M, Liu S, Liu S, Wang H, Dai C, Ye Y, Liu M, Shang L, et al. 2023. Effects of high-water fluoride exposure on IQ levels in school-age children: A cross-sectional study in Jiangsu, China. Expo Health. 16(3):885–895. 10.1007/s12403-023-00597-2
Xiang Q, Liang Y, Chen B, Chen L. 2011. Analysis of children’s serum fluoride levels in relation to intelligence scores in a high and low fluoride water village in China. Fluoride. 44(4):191–194.
Xiang Q, Liang Y, Chen L, Wang C, Chen B, Chen X, Zhou M. 2003 a. Effect of fluoride in drinking water on children’s intelligence. Fluoride. 36(2):84–94.
Xiang Q, Wang Y, Yang M, Zhang M, Xu Y. 2013. Level of fluoride and arsenic in household shallow well water in Wamiao and Xinhuai villages in Jiangsu Province, China. Fluoride. 46(4):192–197.
Xiang QY, Liang YX, Zhou MS, Zang HB. 2003 b. Blood lead of children in Wamiao-Xinhuai intelligence study. Fluoride. 36(3):198–199.
Xu Y, Lu C, Zhang X. 1994. [The effect of fluorine on the level of intelligence in children]. Endemic Dis Bull. 9(2):83–84.
Yang Y, Wang X, Guo X, Hu P. 2008. The effects of high levels of fluoride and iodine on child intellectual ability and the metabolism of fluoride and iodine. Fluoride. 41(4):336–339.
Yang Y, Wang XXG, Hu P. 1994. [The effects of high levels of fluoride and iodine on child intellectual ability and the metabolism of fluoride and iodine]. Chin J Epidemiol. 15(4):296–298.
Yao L, Zhou J, Wang X, Cui Q, Lin F. 1996. Analysis on the correlation between TSH and intelligence in children with dental fluorosis from endemic fluorosis regions. Lit Inf Prev Med. 2(1):26–27.
Yasmin S, Ranjan S, D’Souza D. 2013. Effect of excess fluoride ingestion on human thyroid function in Gaya Region, Bihar, India. Toxicol Environ Chem. 95(7):1235–1243. 10.1080/02772248.2013.847619
Yazdi SM, Sharifian A, Dehghani-Beshne M, Momeni VR, Aminian O. 2011. Effects of fluoride on psychomotor performance and memory of aluminum potroom workers. Fluoride. 44(3):158–162.
Yu X, Chen J, Li Y, Liu H, Hou C, Zeng Q, Cui Y, Zhao L, Li P, Zhou Z, et al. 2018. Threshold effects of moderately excessive fluoride exposure on children’s health: A potential association between dental fluorosis and loss of excellent intelligence. Environ Int. 118:116–124. 10.1016/j.envint.2018.05.042 29870912
Yu X, Xia L, Zhang S, Zhou G, Li Y, Liu H, Hou C, Zhao Q, Dong L, Cui Y, et al. 2021. Fluoride exposure and children’s intelligence: Gene-environment interaction based on SNP-set, gene and pathway analysis, using a case-control design based on a cross-sectional study. Environ Int. 155:106681. 10.1016/j.envint.2021.106681 34098334
Yu YN, Yang WX, Dong Z, Wan CW, Zhang JT, Liu JL, Xiao KQ, Huang YS, Lu BF. 1996. [Neurotransmitter and receptor changes in the brains of fetuses from areas of endemic fluorosis]. Chin J Endemiol. 15(5):257–259.
Yu YN, Yang WX, Dong Z, Wan CW, Zhang JT, Liu JL, Xiao KQ, Huang YS, Lu BF. 2008. Neurotransmitter and receptor changes in the brains of fetuses from areas of endemic fluorosis. Fluoride. 41(2):134–138.
Zhang KL, Lou DD, Guan ZZ. 2015. Activation of the AGE/RAGE system in the brains of rats and in SH-SY5Y cells exposed to high level of fluoride might connect to oxidative stress. Neurotoxicol Teratol. 48:49–55. 10.1016/j.ntt.2015.01.007 25666879
Zhang S, Zhang X, Liu H, Qu W, Guan Z, Zeng Q, Jiang C, Gao H, Zhang C, Lei R, et al. 2015 b. Modifying effect of COMT gene polymorphism and a predictive role for proteomics analysis in children’s intelligence in endemic fluorosis area in Tianjin, China. Toxicol Sci. 144(2):238–245. 10.1093/toxsci/kfu311 25556215
Zhao L, Yu C, Lv J, Cui Y, Wang Y, Hou C, Yu J, Guo B, Liu H, Li L. 2021. Fluoride exposure, dopamine relative gene polymorphism and intelligence: A cross-sectional study in China. Ecotoxicol Environ Saf. 209:111826. 10.1016/j.ecoenv.2020.111826 33360592
Zhao Q, Niu Q, Chen J, Xia T, Zhou G, Li P, Dong L, Xu C, Tian Z, Luo C, et al. 2019. Roles of mitochondrial fission inhibition in developmental fluoride neurotoxicity: Mechanisms of action in vitro and associations with cognition in rats and children. Arch Toxicol. 93(3):709–726. 10.1007/s00204-019-02390-0 30659323
Zhao Q, Tian Z, Zhou G, Niu Q, Chen J, Li P, Dong L, Xia T, Zhang S, Wang A. 2020. SIRT1-dependent mitochondrial biogenesis supports therapeutic effects of resveratrol against neurodevelopment damage by fluoride. Theranostics. 10(11):4822–4838. 10.7150/thno.42387 32308752
Zhou G, Tang S, Yang L, Niu Q, Chen J, Xia T, Wang S, Wang M, Zhao Q, Liu L, et al. 2019. Effects of long-term fluoride exposure on cognitive ability and the underlying mechanisms: Role of autophagy and its association with apoptosis. Toxicol Appl Pharmacol. 378:114608. 10.1016/j.taap.2019.114608 31173788
Zhou G, Zhao Q, Luo C, Liu H, Li P, Cui Y, Yu X, Chen J, Liu L, Zhang S, et al. 2021. Low-moderate fluoride exposure and intelligence among Chinese school-aged children: Role of circulating mtDNA content. Sci Total Environ. 786:147330. 10.1016/j.scitotenv.2021.147330
Zhou T, Duan L, Ding Z, Yang R, Li S, Xi Y, Cheng X, Hou J, Wen S, Chen J, et al. 2012. Environmental fluoride exposure and reproductive hormones in male living in endemic fluorosis villages in China. Life Sci J. 9(4):1–7.
Zohouri FV, Swinbank CM, Maguire A, Moynihan PJ. 2006. Is the fluoride/creatinine ratio of a spot urine sample indicative of 24-h urinary fluoride? Community Dent Oral Epidemiol. 34(2):130–138. 10.1111/j.1600-0528.2006.00269.x 16515677