# Addendum: Updated Literature Search (May 2020 through October 2023)

## Introduction

The multiple scientific peer reviews of this monograph are outlined in Appendix B, Table B-1. During the final stage of review by the NTP Board of Scientific Counselors (BSC), a recommendation was made by the BSC Working Group, which was adopted by the full BSC, to update the literature for this monograph that examined the association between fluoride exposure and children’s IQ. To comply with this recommendation, an update to the May 2020 literature search was completed in October 2023. The updated literature search was conducted using the same methods as those described in the Main Literature Search section of this document and in the protocol (https://ntp.niehs.nih.gov/go/785076).

The results of this updated search are outlined below and are shown in the reference flow diagram (Addendum Figure 1). Six low risk-of-bias studies reported on new cohorts of children (i.e., study populations that had not previously been considered in the confidence assessment of the draft monograph reviewed by the BSC Working Group). Therefore, the results of this updated literature search have been included as this Addendum to the monograph rather than incorporated into the monograph. As such, this Addendum was prepared to describe relevant information from the updated literature search on the association between fluoride exposure and children’s IQ and to discuss any potential impact of this information on the confidence conclusions of the monograph. This Addendum also includes a discussion of meta-analyses of studies examining the relationship between children’s estimated fluoride exposure and IQ to provide further context of the findings from the updated literature search.

In addition to children’s IQ studies, several studies (including Cantoral et al. 2021; and Ibarluzea et al. 2021) were found during the updated literature search that fall under the “Other Neurodevelopmental or Cognitive Effects in Children” or “Cognitive Effects in Adults” outcome categories of the monograph. Therefore, these studies are not discussed in this Addendum; however, they are included in sensitivity analyses in the DTT meta-analysis, which is a separate peer-reviewed journal publication (DTT Meta-analysis, Taylor et al. 2024, in press).

Addendum Figure 1

Reference Flow Diagram for Updated Literature Search^a^

^a^An interactive version of this figure is available here (https://hawcproject.org/summary/visual/assessment/405/Add-Figure-1-Reference-Flow-Diagram-Updated-Lit/).

*Studies may have been excluded for more than one reason; the first reason identified was recorded.

## Results

Twenty-eight studies were published on the association between fluoride exposure and children’s IQ between May 2020 (the end date of the literature search for the monograph) and October 2023 (the date of this updated literature search). Twelve studies (seven cross-sectional and five prospective cohort studies from nine different study populations) had lower potential for bias. Sixteen cross-sectional studies had higher potential for bias (see Addendum Figure 2).

Addendum Figure 2

Risk-of-bias Heatmap for Children’s IQ Studies Identified During Updated Literature Search

An interactive version of this figure is available here (https://hawcproject.org/summary/visual/assessment/405/Figure-2-Addendum/).

### Low Risk-of-bias Studies

The updated literature search identified 12 low risk-of-bias IQ studies in children. None of the new low risk-of-bias studies evaluated populations in the United States.

Six of the 12 low risk-of-bias studies were conducted on populations already discussed in the main portion of the monograph (see Addendum Table 1). Results from these studies (Farmus et al. 2021; Goodman et al. 2022a; Goodman et al. 2022b; Wang et al. 2021c; Yu et al. 2021; Zhou et al. 2021) were similar to the results of the original studies, but included additional analyses and, in some cases, additional mechanistic data.

Three of the studies that evaluated new populations (i.e., did not evaluate populations that overlapped with studies included in the main portion of the monograph) reported statistically significant inverse associations (at p-value < 0.05) between urinary fluoride exposures and children’s IQ (Feng et al. 2022; Zhao et al. 2021). All three were cross-sectional studies conducted in China. Zhao et al. (2021) conducted a cross-sectional study in Tianjin City in 2018 with a stratified multistage random sampling of 6–11-year-olds from five randomly selected primary schools from five randomly selected towns (four with historically high fluoride and one without high fluoride). The study reported a statistically significant inverse association between children’s urinary fluoride (median [Q1–Q3] = 1.03 [0.72–1.47] mg/L) and IQ scores (adjusted β = −5.957, 95% CI: −9.712, −2.202 per 1-log-mg/L increase). Feng et al. (2022) conducted a cross-sectional study in Tongxu County in 2017 that evaluated children in four randomly selected primary schools. Using the median level of creatinine-adjusted urinary fluoride (i.e., 1.33 mg/L), the children were separated into high and control fluoride groups (mean [SD] = 2.15 [0.91] mg/L and 0.83 [0.30] mg/L, respectively). There was a statistically significant inverse association between creatinine-adjusted urinary fluoride and IQ scores in the high fluoride group (adjusted β = −2.502, 95% CI: −4.411, −0.59 per 1-mg/L increase). There were no statistically significant associations among the control group or when the two groups were combined or between the mean IQ scores when comparing the two groups. Xia et al. (2023) conducted a cross-sectional study in Jiangsu Province by selecting three communities with high fluoride (described as >1.0 mg/L) and three control communities with fluoride below 1.0 mg/L based on monitoring results from 2018 to 2019. Mean IQ of primary school children was significantly lower in the high fluoride communities compared to the control communities (p < 0.001). There was a statistically significant inverse association between urinary fluoride and IQ scores in the high fluoride communities (β = −4.08, 95% CI: −3.04, −1.32 per 1-mg/L increase). The risk of below-normal IQ scores increased with excessive urinary fluoride exposure, presence of dental fluorosis, and increases of dental fluorosis grading.

Three of the six studies that evaluated new populations reported non-statistically significant inverse associations between fluoride and children’s IQ. Lin et al. (2023) conducted a cross-sectional study in Taichung, Taiwan from 2019 to 2020 by randomly selecting five elementary schools. Two [struck: children] classes from each grade were invited to participate.^18^ The study reported an inverse association between urinary fluoride and IQ scores (β = −0.97, 95% CI: −2.90, 0.97 per ln-mg/L increase) and creatinine-adjusted urinary fluoride and IQ scores (β = −2.21, 95% CI: −4.99, 0.57 per ln-mg/g increase). Grandjean et al. (2023) conducted a study using the Odense Child Cohort (OCC). Creatinine-adjusted maternal urinary fluoride was inversely associated with full-scale IQ scores of 7-year-old children when using 24-hour maternal urine samples (β = −0.72, 95% CI: −3.24, 1.80 per doubling of maternal urinary fluoride). When using spot urine samples, there was an inverse association with IQ in girls (β = −0.78, 95% CI: −3.64, 2.08) and a positive association with IQ in boys (β = 2.14, 95% CI: −0.92, 5.20). Dewey et al. (2023) was a unique prospective ecological cohort study that evaluated exposures before and after fluoridation ceased in Calgary, Canada on May 19, 2011. Exposure was based on when the pregnancy occurred in relation to when water fluoridation had stopped. Participants were considered fully exposed to 0.7 mg/L fluoride if the women were pregnant the whole time before water fluoridation stopped, partially exposed when part of the pregnancy occurred before water fluoridation stopped, or not exposed if pregnancy began after fluoridation stopped. Using the nonexposed participants as the reference group, this study reported inverse associations between fluoride exposure and verbal comprehension index and visual spatial index in 3–5-year-old children. There were inverse associations between fluoride exposure and full-scale IQ in fully exposed boys (β = −0.71, 95% CI: −5.46, 4.04) compared to nonexposed boys and in partially exposed girls (β = −0.62, 95% CI: −4.67, 3.43) compared to nonexposed girls. In this study, IQ was assessed using the Wechsler Preschool and Primary Scale of Intelligence Fourth Edition: Canadian (WPPSI-IVCND) which does not include a performance IQ score. As noted in the main section of this document, fluoride exposure has been found to be more strongly associated with performance scores compared to other IQ subtests (e.g., verbal IQ) (Green et al. 2019; Till et al. 2020). In addition, the exposure was based solely on fluoridation status during pregnancy and did not consider the quantity of water intake by the mothers or exposure to fluoride from sources other than drinking water.

18 ERRATUM: An error was identified in the NTP Monograph on the State of the Science Concerning Fluoride Exposure and Neurodevelopment and Cognition: A Systematic Review (NTP Monograph 08). This sentence originally read, “Two children from each grade...,” which contained an error. It has been corrected to: “Two classes from each grade...” (and the correction is italicized). [September 4, 2024]

Nine low risk-of-bias studies examined specific aspects of the inverse association between fluoride exposure and children’s IQ. Five of the studies evaluated mechanistic aspects associated with fluoride exposure assessment measures including genetic variants, gene-environment interactions, or effects on the cholinergic system. Other studies assessed the specific timing of exposure (prenatal, infancy, and childhood) (Farmus et al. 2021), evaluated multiple IQ domains (Dewey et al. 2023; Goodman et al. 2022a), or assessed the role of iodine on the association between fluoride exposure and IQ (Goodman et al. 2022b).

Addendum Table 1 Studies on IQ in Children since 2020^a^

Study | Study Design (Location/Subjects) [n] | Exposure Measures and Summary Statistics | Assessment Timing | Outcome and Methods | Summary of IQ Results^b^
China
Xia et al. (2023) | Cross-sectional Jiangsu Province (school children) [711] | Drinking water Overall mean (SD): 1.18 (0.11) mg/L Control group: 0.73 (0.08) mg/L High fluoride group: 1.89 (0.17) mg/L Children’s urine Control group, median (min, max): 0.98 (0.33, 3.59) mg/L High fluoride group: 2.63 (0.57, 8.84) mg/L | Children (ages 8–12 years) | IQ: Combined Raven’s Test for Rural China | Significant inverse association between children’s urinary fluoride and IQ scores in the high fluoride group (adjusted β per 1.0 mg/L = −4.08; 95% CI: −3.04, −1.32). High fluoride group had significantly lower mean IQ scores than the control group (p < 0.001). Adjusted for age, sex, BMI, parental education
Feng et al. (2022) | Cross-sectional Tongxu County, Henan Province (school children) [683] | Children’s urine (creatinine adjusted), mean (SD): 1.49 (0.95) mg/L Control group: 0.83 (0.30) mg/L High fluoride group: 2.15 (0.91) mg/L | Children (ages 8–12 years) | IQ: Combined Raven's Test for Rural China | Significant inverse association between child’s urinary fluoride and IQ scores in the high fluoride group (adjusted β per 1.0 mg/L = −2.502; 95% CI: −4.411, −0.593); probability of having “excellent” IQ were significantly decreased in the high fluoride group (adjusted OR per 1 mg/L = 0.537; 95% CI: 0.290, 0.994); no significant difference in mean IQ scores between the control and high fluoride group. Significant interactions observed between fluoride exposure and methylenetetrahydrofolate dehydrogenase, cyclohydrolase, and formyltetrahydrofolate synthetase 1 (MTHFD1) variants. Adjusted for age, sex, BMI, gestational weeks, maternal and paternal education, birth weight, birth modes, and maternal age at pregnancy
Wang et al. (2021c) Same population as Yu et al. (2018) | Cross-sectional Tianjin City, 7 towns/children [709] | Drinking water, mean (SD): 1.20 (0.95) mg/L Children’s urine: 0.66 (0.67) mg/L | Children (ages 7–13 years) | IQ: Combined Raven’s Test for Rural China | Significant inverse association between fluoride exposures (both water and urine) and IQ scores in both boys and girls (p-values for trend <0.05) Significant inverse association between water fluoride levels >1.0 mg/L and IQ score for all children (adjusted β for Q3 [1.00 – 1.60 mg/L] vs. Q1 [≤ 0.30 mg/L]: −2.77; 95% CI: [−5.44, −0.10; for Q4 [>1.60 mg/L] vs. Q1 [≤ 0.30 mg/L] −4.10; 95% CI: −6.71, −1.48). Significant inverse association between urinary fluoride levels and IQ score for all children (adjusted β for Q3 [0.48–0.90 mg/L] vs. Q1 [≤ 0.20 mg/L]: −3.02; 95% CI: –5.71, –0.33; for Q4 [>0.90 mg/L] vs. Q1 [≤ 0.20 mg/L]: −4.49; 95% CI: −7.21, −1.77). Significantly reduced probabilities of superior and above IQ (≥120) for both water fluoride (adjusted OR per 1 mg/L: 0.69; 95% CI: 0.54, 0.90) and urinary fluoride (OR per 1 mg/L: 0.67; 95% CI: 0.46, 0.97). Water fluoride was significantly positively associated with serum AChE and significantly negatively associated with serum ChAT and ACh; trends were similar for urinary fluoride, except ACh did not have a statistically significant trend. Adjusted for age, sex, BMI, low birth weight, maternal and paternal education, family income, and urine creatinine (for urinary fluoride)
Yu et al. (2021) Same population as Yu et al. (2018) | Cross-sectional Tianjin City, 7 towns/children [952] High IQ (IQ ≥120) [173] Non-high IQ (70≤IQ<120) [779] | Drinking water, median (Q1–Q3) High IQ group: 0.70 (0.40–1.00) mg/L Non-high IQ group: 1.00 (0.50–1.90) mg/L Children’s urine High IQ group: 0.33 (0.13–0.81) mg/L Non-high IQ group: 0.60 (0.16–2.22) mg/L Children’s hair High IQ group: 8.26 (5.72–10.48) µg/g Non-high IQ group: 14.39 (10.25–20.56) µg/g Children’s nail High IQ group: 11.71 (8.53–14.64) µg/g Non-high IQ group: 19.76 (14.16–27.32) µg/g | Children (ages 7–13 years) | IQ: Combined Raven’s Test for Rural China | Higher fluoride associated with lower probability of high IQ for all 4 exposure matrices (p-values for trend <0.001). Water: adjusted OR for tertile 2 (0.61–1.40 mg/L) vs. tertile 1 (≤60 mg/L): 0.94; 95% CI: 0.64, 1.37; for tertile 2 (>1.40 mg/L) vs. tertile 1 (≤60 mg/L): 0.39; 95% CI: 0.25, 0.61. Urine: adjusted OR for tertile 2 (0.23–1.80 mg/L) vs. tertile 1 (≤0.22 mg/L): 1.26; 95% CI: 0.87, 1.84; for tertile 3 (>1.80 mg/L) vs. tertile 1 (≤0.22 mg/L): 0.41; 95% CI: 0.26, 0.66. Significant inverse association between fluoride exposures and IQ scores for all 4 matrices (water and urine data below). Water, adjusted β per 0.5-mg/L increase in water fluoride at levels between 0.20–3.40 mg/L: −1.16; 95% CI: −1.41, −0.91; at levels between 3.40–3.90 mg/L: −4.21; 95% CI: −7.54, −0.87. Urine, adjusted β per 0.5-mg/L increase in urinary fluoride at levels between 0.01–1.60 mg/L: 1.01; 95% CI: 0.34, 1.68; at levels between 1.60–2.50 mg/L: −5.23; 95% CI: −7.07, −3.39); at levels between 2.50–5.54 mg/L: −0.34; 95% CI: −0.98, 0.30. Significant interactions between water, urinary and hair fluoride exposures and a SNV set of 5 genes related to neurodevelopment or mitochondrial function. Adjusted for age, sex, maternal and paternal education
Zhao et al. (2021) | Cross-sectional Tianjin City, 5 towns (school children) [567] | Children’s urine, median (Q1–Q3): 1.03 (0.72–1.47) mg/L Log-transformed urine, Mean (SD): 0.015 (0.252) | Children (ages 6–11 years) | IQ: Combined Raven's Test for Rural China | Significant inverse association between urinary fluoride and IQ scores (adjusted β per 1-log-mg/L = −5.957; 95% CI: −9.712, −2.202). Interactions with dopamine-related genes (COMT, ANKK1, DAT1, and MAOA) were also observed. Adjusted for age, sex, BMI, maternal and paternal education, household income, abnormal birth, and maternal age at delivery
Zhou et al. (2021) Same population as Yu et al. (2018) | Cross-sectional Tianjin City, 30 villages/children [605] | Drinking water, median (Q1–Q3) Moderate fluoride group: 2.20 (1.50–2.80) mg/L Normal fluoride group: 0.70 (0.40–0.70) mg/L Children’s urine Moderate fluoride group: 2.29 (1.94–2.88) mg/L Normal fluoride group: 0.15 (0.08–0.27) mg/L | Children (ages 7–13 years) | IQ: Combined Raven’s Test for Rural China | Significant inverse association between fluoride exposure and IQ scores: Water: adjusted β per 1-mg/L increase = −1.29; 95% CI: −2.05, −0.52) Urine: adjusted β per 1-mg/L increase = −0.75; 95% CI: −1.35, −0.15) Significant inverse association between water and urine fluoride exposures and circulating mitochondrial DNA (mtDNA). Significantly increased odds of excellent intelligence in children in the highest tertile of mtDNA compared to children in the lowest tertile. Significant association between mtDNA and higher odds of having excellent intelligence in girls only. No significant association between mtDNA and children’s IQ scores. Adjusted for age, sex, BMI, low birth weight, household income, maternal and paternal education
Taiwan
Lin et al. (2023) | Cross-sectional Taichung (school children) [562] | Children’s urine, mean (SD) Reference: 0.38 (0.25) mg/L Dental fluorosis: 0.46 (0.32) mg/L | Children (ages 6–12 years) | IQ: Raven’s Colored Progressive Matrices-Parallel, Taiwan edition | No significant associations between children’s urinary fluoride exposure or dental fluorosis and children’s IQ; nonsignificant inverse association between urinary fluoride and IQ scores (adjusted β per ln-mg/L increase = −0.97, 95% CI: −2.90, 0.97) and creatinine-adjusted urinary fluoride and IQ scores (β per ln-mg/g increase = −2.21, 95% CI: −4.99, 0.57). Adjusted for age, area of school, BMI, sex, history of allergic rhinitis, parental education
Mexico
Goodman et al. (2022a) Same population as Bashash et al. (2017) | Cohort (prospective) Mexico City/Early Life Exposures in Mexico to Environmental Toxicants (ELEMENT) participants [348] IQ analysis [278] | Maternal urine during pregnancy (creatinine adjusted), mean (SD): 0.90 (0.39) mg/L | Children (ages 6–12 years) | Full-scale, performance, and verbal IQ: WASI, Spanish Version | Significant inverse associations between maternal urinary fluoride and child’s full scale IQ score (adjusted β per 0.5-mg/L = −2.01; 95% CI: −3.66, −0.46); performance IQ (adjusted β per 0.5-mg/L = −1.80; 95% CI: −3.39, −0.21); and verbal IQ (adjusted β per 0.5-mg/L = −1.93; 95% CI: −3.67, −0.18). Adjusted for gestational age, birth weight, sex, parity (being the first child), age at outcome measurement, time of testing and maternal characteristics including smoking history, marital status, age at delivery, education, maternal education, and cohort
Denmark
Grandjean et al. (2023) | Cohort (prospective) Odense Child Cohort, Odense [837] IQ analysis [460] Boys [239], girls [221] | Maternal urine (creatinine adjusted), mean (SD): 0.58 (0.32) mg/L | Children (age 7 years) | Full-scale IQ: Wechsler Intelligence Scales for Children, Danish version | No significant associations between maternal urinary fluoride exposure and full-scale IQ; however, there was an inverse association for 24-hr urine samples (adjusted β per doubling of maternal urinary fluoride = −0.72, 95% CI: −3.24, 1.80). Spot urine samples had a nonsignificant inverse association with IQ in girls (β per doubling of maternal urinary fluoride = −0.78, 95% CI: −3.64, 2.08) and a nonsignificant positive association with IQ in boys (β per doubling of maternal urinary fluoride = 2.14, 95% CI: −0.92, 5.20). Adjusted for parental education, preterm birth, age at the time of testing, examiner, breastfeeding duration, school grade, school type, smoking status, alcohol consumption
Canada
Dewey et al. (2023) | Cohort (prospective ecological) APrON Cohort, Calgary [616] | Not exposed/partially exposed/fully exposed to fluoridated drinking water (0.7 mg/L) during pregnancy Exposure groups based on when the pregnancy occurred in relation to when water fluoridation had stopped. | Children (ages 3−5 years) | Full-scale IQ: Wechsler Preschool and Primary Scale of Intelligence, Fourth Edition (WPPSI-IV CND) | No significant associations between fluoride exposure and full-scale IQ.
Farmus et al. (2021) Same population as Green et al. (2019) and Till et al. (2020) | Cohort (prospective) 6 of 10 cities/Maternal-Infant Research on Environmental Chemicals (MIREC) [596] Maternal urine [593] Infant fluoride intake [442] Children’s urine [434] Boys [291], girls [305] | Maternal urine during pregnancy. mean (SD) 0.53 (0.37) mg/L First trimester: 0.44 (0.46) mg/L Second trimester: 0.51 (0.48) mg/L Third trimester: 0.65 (0.53) mg/L Infant fluoride intake: 0.14 (0.13) mg/day Children’s urine: 0.51 (0.39) mg/L | Children (ages 3−4 years) | Full-scale, performance, and verbal IQ: Wechsler Preschool and Primary Scale of Intelligence, Third Edition (WPPSI-III) | Significant inverse associations between maternal urinary fluoride and full-scale IQ in boys (adjusted β per 0.5-mg/L = −2.48; 95% CI: −4.30, −0.66) and for performance IQ in boys and all children (adjusted β per 0.5-mg/L = −4.02; 95% CI: −6.15, −1.89 and adjusted β per 0.5-mg/L = −3.15; 95% CI: −4.85, −1.44, respectively). No significant associations between maternal urinary fluoride and full-scale IQ and performance IQ in girls (adjusted β per 0.5-mg/L = −0.31; 95% CI: −2.76, 2.14 and adjusted β per 0.5-mg/L = −1.58; 95% CI: −4.43, 1.28, respectively). Significant inverse associations between infant fluoride intake and performance IQ in girls (adjusted β per 0.1-mg/day = −2.03; 95% CI: −3.43, −0.63) and all children (adjusted β per 0.1-mg/day = −1.58; 95% CI: −2.59, −0.57). No significant associations between fluoride exposure measures (maternal urine, child urine or infant intake) and verbal IQ. No significant associations between child’s urinary fluoride levels and full-scale, performance or verbal IQ scores. Adjusted for HOME score, maternal education, race, age at urine sampling, and prenatal secondhand smoke exposure
Goodman et al. (2022b) Same population as Green et al. (2019) and Till et al. (2020) | Cohort (prospective) 6 of 10 cities/Maternal-Infant Research on Environmental Chemicals (MIREC) [601] Maternal urine [366] Boys [186] Girls [180] | Maternal urine during pregnancy (corrected for creatinine), median (IQR): 0.61 (0.49) mg/g Boys: 0.63 (0.52) mg/g Girls: 0.61 (0.48) mg/g | Children (ages 3−4 years) | Full-scale IQ: Wechsler Preschool and Primary Scale of Intelligence, Third Edition (WPPSI-III) | Significant inverse association between maternal urinary fluoride and full-scale IQ (adjusted β [SE] per 0.5-mg/g creatinine = −5.89 [1.85]). Significant 3-way interaction between maternal urinary fluoride, maternal urinary iodine, and child’s sex for full-scale IQ; significant interaction between maternal urinary fluoride and maternal urinary iodine in boys, but not girls; in boys, low maternal urinary iodine was associated with a larger decrease in full-scale IQ compared with boys whose mothers had adequate iodine (adjusted β per 0.5 mg/g creatinine: −4.65 and −2.95, respectively). Adjusted for maternal education, maternal race, study site, and HOME score

HOME = Home Observation Measurement of the Environment; IQ = intelligence quotient; IQR = interquartile range; OR = odds ratio; Q1, Q3 = first and third quartiles; SD = standard deviation; SNV = single nucleotide variant; WASI = Wechsler Abbreviated Scale of Intelligence (Spanish version); WPPSI = Wechsler Preschool and Primary Scale of Intelligence.

^a^ Includes low risk-of-bias studies only.

^b^ Associations between fluoride assessment measures and IQ were reported quantitatively, when possible. For studies with multiple analyses and results, the table summarizes key findings and is not a comprehensive summary of all findings reported in the study. Results also indicate when a study reported no significant association between fluoride assessment measures and IQ.

### High Risk-of-bias Studies

There were 16 high risk-of-bias IQ studies in children published since the last literature search update. Thirteen of the 16 studies reported an inverse association between fluoride exposure and IQ in areas of China (6 studies), India (5 studies), Indonesia (1 study), and Pakistan (1 study). Among the three studies that did not report an inverse association between fluoride exposure and IQ, one study conducted in the Dominican Republic reported that, “Almost 99% of the evaluated students [living in an area of endemic fluorosis] got intellectually lower results than the average score according to Raven’s test” and that there was no statistically significant difference in IQ percentiles across dental fluorosis scores. One study in Pakistan reported significantly higher IQ scores in urban areas with higher fluoride compared with IQ scores in rural areas with lower fluoride. One study in India reported that there was no significant association between fluoride levels above and below 0.5 ppm and risk of low intelligence level in adolescents ages 10 to 14 years.

### Human Mechanistic Studies of Fluoride and Cognitive Neurodevelopment

Although multiorgan toxicity of fluoride has long been recognized (IPCS 2002), there remains no clear established mechanism for fluoride’s adverse effect on cognitive neurodevelopment (Li et al. 2023). This is not due to a lack of potential mechanisms, but more likely due to the myriad of ways that fluoride and fluoride complexes affect fundamental cellular biochemistry. These include, but are not limited to, binding to and inhibiting enzymes involved in intermediary metabolism and cell signaling, disrupting organelle structure and function (particularly of mitochondria), and altering electrolyte balance and cellular pH. Nonetheless, the contribution of these mechanisms to neurotoxicity at current levels of fluoride exposure to humans has been questioned (reviewed in Johnston and Strobel 2020).

Five of the low risk-of-bias studies identified in this updated literature search explored potential mechanisms of fluoride effects on children’s IQ (Feng et al. 2022; Wang et al. 2021c; Yu et al. 2021; Zhao et al. 2021; Zhou et al. 2021). Many of the mechanistic studies that are reviewed in the main body of this monograph examined deficits in thyroid hormones associated with higher fluoride exposures. Although not directly related to the question of fluoride’s effect on thyroid function, one new study (Goodman et al. 2022b) noted a larger deficit in IQ for a 0.5-mg/g increase in maternal urinary fluoride exposure for boys born to mothers whose urinary iodine levels were low compared with boys born to mothers whose urinary iodine levels reflected an adequate iodine intake.

An earlier high risk-of-bias study by Pratap et al. (2013) [reviewed in the monograph main text] reported lower IQ scores and reduced serum acetylcholinesterase (AChE) activities for children in areas with water fluoride levels above 2.0 ppm compared with control children living in areas with water fluoride less than 1.5 ppm. In contrast, a recent study by Wang et al. (2021c) reported that serum AChE was significantly increased in children with higher measures of fluoride in their drinking water or urine and was associated with lower IQs. The Wang et al. (2021c) study also looked at serum choline acetyl transferase (ChAT) and acetylcholine (ACh) levels and reported significant inverse associations between serum ChAT and ACh levels and children’s drinking water and urine fluoride measures, but associations with IQ were not significant. Assuming that ChAT and its degradation enzyme (AChE) levels reflect those in the brain, the findings from Wang et al. (2021c) are more consistent with current concepts of the central role of adequate brain acetylcholine-mediated neurotransmission in learning and memory (Huang et al. 2022) and are inconsistent with the findings reported in Pratap et al. (2013).

Three studies have examined possible relationships between fluoride exposure and dopamine metabolism. A study by Zhang et al. (2015b) [reviewed in the monograph main text] examined the interaction between fluoride exposure and genetic variants of the catechol-O-methyltransferase (COMT) gene, which is partially responsible for dopamine degradation. The study reported a stronger inverse association between measures of fluoride exposure and IQ in children with the reference COMT gene variant (val/val) that exhibited lower activity, and presumably higher brain dopamine levels, than among children who carried the heterozygous or homozygous variant genotypes (met/val or met/met). Cui et al. (2018) [also reviewed in the monograph] reported that an inverse association between fluoride exposure and children’s IQ was found only in children homozygous for the TT variant genotype of the dopamine receptor-2 Taq 1A variant and not in children with the hybrid-type CT or wild-type CC genotypes. The TT genotype is associated with the greatest D2 receptor availability (McDonell et al. 2018).

In a recent study of school-based children from endemic and non-endemic fluorosis areas in Tianjin, China—not related to the Yu et al. (2018) study population in the same area—Zhao et al. (2021) examined genetic variants of several dopamine-related genes as effect modifiers of the inverse association between fluoride exposure and IQ. The study evaluated high and low activity variants of genes thought to be involved in dopamine synthesis (ANKK1 Taq1A), reuptake (DAT1 40 bp VNTR), and catabolism (COMT Val158Met and MAOA uVNTR). The study observed no interactions between urinary fluoride and variants of the single genes but found a high-dimensional interaction on IQ among urinary fluoride, ANKK1, COMT, and MAOA, and concluded that dopamine-related pathways may play a critical role in the neurotoxicity of fluoride. Overall, the three studies discussed above provide evidence that the inverse association between fluoride exposure and children’s IQ may involve or interact with genetic differences in dopamine-related pathways.

Feng et al. (2022) examined possible interactions between fluoride exposure measures and children’s genetic variants in four specific loci in the multifunctional enzyme complex MTHFD1 (methylenetetrahydrofolate dehydrogenase, cyclohydrolase, formyltetrahydrofolate synthetase 1), which functions in folate metabolism, on the intelligence of children living in areas of endemic fluorosis. This potential interaction was of interest to the authors because folate deficiency is believed to be associated with neuropathological lesions. The study did not find evidence of an interaction with any single locus but observed evidence of interactions between multiple loci in several different statistical models, suggesting that “MTHFD1 polymorphisms may be involved in the effects of fluoride exposure on intelligence in school-age children.”

Yu et al. (2021) examined potential interactions of genetic variants associated with nervous system development and mitochondrial processes with fluoride-induced deficits in IQ in a subset of children from Tianjin, China (also part of Yu et al. 2018 study). There were 53 functional single nucleotide variants (SNVs) from 17 candidate genes selected for analysis. Of the 53 SNVs, 5 were on genes [catechol-O-methyl transferase (COMT), nitric oxide synthase1 (NOS1), translocase of outer mitochondrial membrane (TOMM40), mitochondrial translational elongation factor (TUFM), SLC25A12] that gave an SNV-set score associated with lower IQ. No single gene was found associated with high intelligence, but clusterin protein (CLU) and translocase of outer mitochondrial membrane 40 (TOMM40) interacted significantly with IQ and fluoride measurements in hair of females. Pathway analyses did not show significant interactions with fluoride exposures and IQ.

Zhou et al. (2021) evaluated mitochondrial DNA (mtDNA) copy number in relation to single-copy nuclear DNA in lymphocytes and its potential role in the inverse association between fluoride exposure measures and IQ in a subset of children from Tianjin, China (also part of Yu et al. 2018 study). The study observed a significantly downward trend between mtDNA copy number across tertiles of fluoride drinking water and urine measures. There were significantly increased odds of having excellent intelligence in children in the highest tertile of mtDNA compared with children in the lowest tertile, and a significant association between mtDNA and higher odds of having excellent intelligence was found in girls, but not in boys. However, there was no significant association between circulating mtDNA levels and children’s IQ scores. The authors noted that further research is needed to characterize the relationship between mtDNA content in peripheral blood and mtDNA content in neuronal tissues.

The studies outlined above provide valuable additional mechanistic information, potential insights, and further suggestive evidence that there may be genetic variants that may affect the susceptibility of some individuals to greater cognitive impairment than others associated with exposures to fluoride during development. However, a clear mechanism for a fluoride effect on cognitive neurodevelopment remains to be established.

### Meta-analyses on Fluoride Exposure and Children’s IQ

Seven meta-analyses found statistically significant inverse associations between fluoride assessment measures and children’s IQ (Addendum Table 2). Many of the studies included in these meta-analyses lacked the information necessary to evaluate study quality, and most used group-level estimates of fluoride exposure. The meta-analyses used a range of methods and varied in the transparency, objectivity (e.g., predefined protocol), and rigorousness of the analytic approaches applied, including procedures such as: study selection, quantitative evaluation of overall associations, and selection of effect measures. For the effect measure, four meta-analyses used a standardized mean difference (SMD) (Choi et al. 2012; DTT Meta-analysis, Taylor et al. 2024, in press; Duan et al. 2018; Kumar et al. 2023), two used weighted mean difference (WMD) (Tang et al. 2008; Veneri et al. 2023), and one used an odds ratio (Miranda et al. 2021).

Tang et al. (2008) conducted a meta-analysis of 16 case-control studies with a pooled WMD calculated using the Mantel-Haenszel method. The study reported significant inverse associations that indicate “children who live in a fluorosis area have five times higher odds of developing low IQ than those who live in a non-fluorosis area or a slight fluorosis area.” The authors’ interpretation of the WMD as “odds of developing low IQ” is lacking because the WMD compares mean differences in IQ scores, not probabilities. Other limitations of this analysis included incorrect statements on study design assignment (all included studies are cross-sectional, not case-control as labeled in the analysis); lack of investigation of sources of heterogeneity (I^2^ not reported or incorrectly listed as “not applicable”); unclear choice of sensitivity analyses; and no reporting of a predefined protocol or software used for the analyses.

Choi et al. (2012) assessed 27 studies comparing mean IQ scores in high fluoride exposure groups to those in low fluoride exposure groups. Most of these study populations were from China and were exposed to fluoride through drinking water. Choi et al. (2012) found an inverse association between fluoride exposure and IQ in children (Addendum Table 2). In meta-regression analyses, the study found that year of publication (but not mean age of the study children) was a significant source of heterogeneity. When the analyses were restricted to the 16 studies that used the Combined Raven’s Test–The Rural edition in China (CRT-RC), the mean age of the study children (but not year of publication) was a significant predictor of the estimated SMD. While the study estimated a risk ratio for living in an endemic fluorosis area, authors excluded studies with individual-level measures of exposure and were not able to perform a formal dose-response analysis. Although software used for the meta-analysis was reported, the study lacked a predefined protocol.

A more recent meta-analysis (Duan et al. 2018) assessed 26 studies that evaluated intelligence levels in children exposed to high or low drinking water fluoride, including 15 that were also included in the Choi et al. (2012) meta-analysis and 7 that were published after the 2011 inclusion period from Choi et al. (2012). Thirteen studies included in the Choi et al. (2012) meta-analysis were not considered in the Duan et al. (2018) evaluation for unclear reasons. The Duan et al. (2018) study included four studies from Iran and four studies from India, with the remaining studies conducted in China. Duan et al. (2018) found an inverse association between fluoride exposure and IQ in children (Addendum Table 2). In meta-regression analyses, the mean age of study children significantly affected the relationship between high water fluoride levels and children’s intelligence levels. Subgroup analyses included country, age (<10 or ≥10 years), water fluoride level, type of intelligence assessment, and sex. Duan et al. (2018) also performed a dose-response meta-analysis that suggested a significant association between increased water fluoride exposure and lower intelligence levels; however, it is unclear which studies were included in this analysis. The study reported both linear and nonlinear inverse relationships between fluoride exposure and children’s intelligence levels. Software used in the meta-analysis was reported; however, the study lacked a predefined protocol.

Miranda et al. (2021) performed a meta-analysis of 10 studies and found an association between high fluoride exposure and decreased IQ as reflected by odds ratios (Addendum Table 2). The meta-analysis has many serious methodological and reporting limitations. Regardless of how the original studies reported the data, Miranda et al. (2021) chose to “classify the studies according to the WHO guidelines that consider optimal levels between 0.5–1.0 mg/L (low levels) and > 2 mg/L, as higher levels for water fluoridation” thus limiting the body of evidence to the few studies reporting the “optimal” low levels, and also excluding studies that reported exposure levels qualitatively (e.g., just described as high and low). In addition, only “low risk of bias” studies were included, and study selection raises serious concerns since many relevant studies were excluded. Other limitations included inappropriate risk-of-bias assessment methodology (i.e., best practices were not followed, and no rationale presented to support ratings that were reported); improper conduct of the quantitative analysis; and use of an effect measure that is limited in its interpretation and usefulness for assessing fluoride-IQ associations.

Veneri et al. (2023) performed a meta-analysis of 30 studies using the WMD as an effect measure. The study reported significant inverse associations between fluoride exposure and IQ in children (Addendum Table 2). There are several concerns with and limitations of this meta-analysis. When the outcome assessment approaches are not identical—such as when IQ is measured with various tests with different scales—a WMD is not an appropriate effect measure (as compared to the SMD which accounts for test heterogeneity). Most importantly, the overall pooled WMD is not valid. Several studies are counted multiple times for each exposure measure of fluoride provided in the study (that result in the same WMD) with no evidence that the correlation between study-specific effects was considered. This occurs for 6 of the 30 included studies (Ahmad et al. 2022; Broadbent et al. 2015; Trivedi et al. 2007; Wang et al. 2021c; Yu et al. 2021; Zhang et al. 2015b). For example, identical estimates from the same study (Zhang et al. 2015b) were included in the overall WMD calculation for three different exposure metrics (water, serum and hair). Another limitation is lack of adequate justification for not considering or including several studies that would appear to meet their inclusion criteria (Farmus et al. 2021; Goodman et al. 2022a; Rocha-Amador et al. 2007). In addition, although the study research question explicitly called for a separate assessment of prenatal exposure, and several studies had maternal urinary fluoride measures, there is no analysis of prenatal fluoride exposure. There is also no discussion of heterogeneity or evidence to indicate that sources of heterogeneity were investigated using stratified analyses or meta-regression.

The Veneri et al. (2023) study also conducted a dose-response meta-analysis which suggested a significant association between increased water or urinary fluoride exposure and lower intelligence levels. However, the lack of detailed discussion of the shape of the dose-response association at levels <1.5 mg/L (WHO Guidelines for Drinking-water Quality) or <0.7 mg/L is a major limitation, especially given the current discourse about the association between fluoride exposure and children’s IQ at lower levels of exposure.

Lastly, for assessing risk of bias, Veneri et al. (2023) employ the ROBINS-E tool (Higgins et al. 2024). This tool uses an algorithm to determine an individual study’s overall risk of bias, which is based on the domain with the greatest risk of bias. For example, if one domain receives a judgement of “high” risk of bias, the study is determined to be “high” risk of bias overall. This approach assumes, without supporting evidence, that each type of bias has an equal influence which may distort true study quality measures. Approaches that give different types of biases equal weight or influence are discouraged by the National Academies of Science (http://bit.ly/2CbAd1A) and others (Jüni et al. 1999; Singla et al. 2019; Stang 2010) as they hinder a more thoughtful and informative critical examination of the evidence and do not acknowledge that some potential biases are more important and influential than others (Arroyave et al. 2021; Savitz et al. 2019; Steenland et al. 2020). In contrast, the OHAT approach is consistent with Cochrane guidance (Sterne et al. 2023) in which studies may be considered “lower” risk of bias (as compared to “higher” risk of bias) based on concern for bias on key domains (e.g., exposure assessment, outcome assessment, confounding) which are determined on a project-specific basis. Veneri et al. (2023) cautioned that the observational design of the reviewed studies may have resulted in unmeasured or residual confounding, reducing confidence in the associations. Although we agree that unmeasured or residual confounding may be a concern, when assessing the impact of each covariate in the DTT Meta-analysis, Taylor et al. (2024, in press), we carefully considered this issue and found that no trends were discernable, suggesting that bias due to confounding could explain the consistency of the inverse association across the body of evidence.

Kumar et al. (2023) performed a meta-analysis of 28 studies using SMD as an effect measure. The study reported significant inverse associations between fluoride exposure and children’s intelligence measures (IQ and cognition scores) (Addendum Table 2). The analysis included double counting of three studies that contributed data to both endemic and nonendemic fluoride areas (i.e., per Kumar et al. (2023) “> and < ~1.5 mg/L fluoride levels” respectively) (Sebastian and Sunitha 2015; Xiang et al. 2003a; Xu et al. 1994). When restricting analyses to eight studies from the nonendemic fluorosis area, the study found no significant associations. There was also no significant association in nonlinear modeling with restricted cubic splines. Meta-analyses of regression coefficients from studies with children’s and maternal urinary fluoride found nonsignificant inverse associations. There are several serious concerns and limitations of these analyses which failed to report many details critical to the conduct of a systematic literature review and meta-analysis. These missing details include, but are not limited to: lacking a predefined protocol; providing rationale or criteria for the risk-of-bias assessments; providing details about how the SMDs were calculated; reporting the data from the individual studies that were used to calculate the SMDs; describing the selection process for which data to use if a study reported results of multiple models; describing assessment of heterogeneity (other than reporting I^2^ values); describing the method for assessment of publication bias; and describing rationale for choice of sensitivity analyses.

The DTT Meta-analysis, Taylor et al. (2024, in press)^19^ includes a meta-analysis and dose-response meta-analysis using group-level exposure data, and a regression slopes meta-analysis using individual-level exposure data. The group-level meta-analysis of 59 studies (n = 20,932 children) used SMD as the effect measure and reported statistically significant inverse associations between fluoride exposure measures and children’s IQ. There was also a significant dose-response relationship between group-level fluoride exposure and IQ. In stratified dose-response meta-analyses of the low risk-of-bias studies, the direction of association remained consistent when group-level exposure was restricted to <4 mg/L, <2 mg/L, and <1.5 mg/L fluoride in drinking water and <4 mg/L, <2 mg/L, and <1.5 mg/L fluoride in urine. The regression slopes meta-analysis of 13 studies (n = 4,475 children) with individual-level measures of fluoride found a significant decrease in IQ of 1.63 points (95% CI: −2.33, −0.93; p-value <0.001) per 1-mg/L increase in urinary fluoride. In subgroup analyses of both group-level and individual-level data, the direction of the association remained inverse when stratified by study quality (high versus low risk of bias), sex, age group, outcome assessment, study location, exposure timing, and exposure metric.

19 The NTP authors of this monograph conducted a companion systematic review and meta-analysis of fluoride exposure and children’s IQ. Reference to this meta-analysis is cited in this monograph as “(DTT Meta-analysis, Taylor et al. 2024, in press).”

Although the use of various effect measures and methods makes comparison of the magnitude of the associations difficult across meta-analyses, there is a consistent reporting of inverse associations between fluoride exposure assessment measures and children’s IQ.

Addendum Table 2 Previous Meta-analyses on Exposures to Fluoride and Children’s IQ

Analysis | Number of Studies | Pooled Effect Type, Estimate (95% CI) | Heterogeneity
Analysis | Number of Studies | Pooled Effect Type, Estimate (95% CI) | p-value | I^2^
Tang et al. (2008) | 16 | WMD, −5.03 (−6.51, −3.55) | NR | NR
Choi et al. (2012) | 27 | SMD, −0.45 (−0.56, −0.34) | <0.001 | 80%
Duan et al. (2018) | 26 | SMD, −0.52 (−0.62, −0.42) | <0.001 | 69.1%
Miranda et al. (2021) | 10 | OR, 3.88 (2.41, 6.23) | <0.0001 | 77%
Veneri et al. (2023) | 30 (38 results) | WMD, −4.68 (−6.45, −2.92) | NR | 98.75%
Kumar et al. (2023) | 28 (31 results) | SMD, −0.33 (−0.44, −0.22) | <0.001 | 83%
DTT Meta-analysis, Taylor et al. (2024, in press) ^a^ | 59 | SMD, −0.45 (−0.57, −0.33) | <0.001 | 94%

CI = confidence interval; NR = not reported; SMD = standardized weighted mean difference; OR = odds ratio of low IQ in the high fluoride versus low fluoride groups; WMD = weighted mean difference.

^a^ The NTP authors of this monograph conducted a companion systematic review and meta-analysis of fluoride exposure and children’s IQ (DTT Meta-analysis, Taylor et al. 2024, in press).

## Conclusion

The current monograph concludes with moderate confidence that higher estimated fluoride exposures (e.g., as in approximations of exposure such as drinking water fluoride concentrations that exceed the WHO Guidelines for Drinking-water Quality of 1.5 mg/L of fluoride) are consistently associated with lower IQ in children. The moderate confidence in the inverse association between fluoride exposure and children’s IQ is based primarily on studies with estimated fluoride exposures higher than what is generally associated with consumption of optimally fluoridated water in the United States.

Compared to the body of literature reviewed in the current monograph that supports the existing confidence statement, the studies identified in the updated literature search had similar study designs and patterns of findings. Recent meta-analyses of the inverse association between children’s IQ and fluoride exposures provide additional evidence of a dose-response relationship. However, uncertainty remains in findings at the lower fluoride exposure range. As this body of evidence matures, consideration for upgrading the moderate confidence conclusion to high confidence based on additional evidence of dose-response relationships at lower fluoride levels may be warranted.