# Summary

This systematic review evaluated the available animal and human literature concerning the association between fluoride exposure and cognitive neurodevelopment. The available data on potential mechanisms to evaluate biological plausibility were also assessed. Existing animal studies provide little insight into the question of whether fluoride exposure affects IQ. Human mechanistic studies were too heterogenous and limited in number to make any determination on biological plausibility. The body of evidence from studies on adults is also limited and provides [underlined: low confidence] that fluoride exposure is associated with adverse effects on adult cognition. There is, however, a large body of evidence on inverse associations between total fluoride exposure and IQ in children. There is also some evidence that higher fluoride exposure is associated with other neurodevelopmental and cognitive effects; although, because of the heterogeneity of the outcomes, there is [underlined: low confidence] in the literature for these other effects.

This review finds, with [underlined: moderate confidence], that higher estimated fluoride exposures (e.g., as in approximations of exposure such as drinking water fluoride concentrations that exceed the World Health Organization Guidelines for Drinking-water Quality of 1.5 mg/L of fluoride) are consistently associated with lower IQ in children. The moderate confidence in the inverse association between fluoride exposure and children’s IQ is based primarily on studies with estimated fluoride exposures higher than what is generally associated with consumption of optimally fluoridated water in the United States. Associations between lower total fluoride exposure [e.g., as in approximations of exposure such as drinking water fluoride concentrations that were lower than the WHO Guidelines for Drinking-water Quality of 1.5 mg/L of fluoride (WHO 2017)] and children’s IQ remain unclear. However, because people receive fluoride from multiple sources (not just drinking water), individuals living in areas with optimally fluoridated water can have total fluoride exposures higher than the concentration of their drinking water. In addition, there are people living in the United States who live in areas with naturally occurring fluoride in drinking water that is higher than 1.5 mg/L. As of April 2020, community water systems supplying water with ≥1.5 mg/L naturally occurring fluoride served 0.59% of the U.S. population (~1.9 million people) (CDC Division of Oral Health 2020). This indicates that the moderate confidence in the inverse association between fluoride exposure and children’s IQ is relevant to some children living in the United States, including at a minimum those living in areas where fluoride in drinking water is known to be at or above 1.5 mg/L.

Additional exposures to fluoride from other sources would increase total fluoride exposure. The moderate confidence conclusions may also be relevant to people living in optimally fluoridated areas of the United States depending on the extent of their additional exposures to fluoride from sources other than drinking water. Because no studies of fluoride exposures and IQ have been performed in children in the United States and no nationally representative urinary fluoride levels are available, targeted research that prospectively examines the association between fluoride exposure and children’s IQ in optimally fluoridated areas of the United States is needed to add clarity to the existing data.