# Discussion

This systematic review evaluated the available animal and human literature concerning the association between fluoride exposure and cognitive neurodevelopment. The available data on potential mechanisms to evaluate biological plausibility were also assessed. The health benefits of fluoride with respect to oral health are acknowledged but are not the focus of this review.

This review extended NTP’s previous evaluation of the experimental animal data (NTP 2016). Although the animal data provide some evidence of effects of fluoride on neurodevelopment, they give little insight into the question of whether fluoride influences IQ. This is due to deficiencies identified in the animal body of evidence. Mechanistic studies in humans provide some evidence of adverse neurological effects of fluoride. However, these studies were too heterogenous and limited in number to make any determination on biological plausibility. Mechanistic studies in animals also provide some evidence of consistency in mechanistic effects (Appendix F); however, the mechanisms underlying fluoride-associated cognitive neurodevelopmental effects are not well characterized, and review of the data did not identify a mode of action for fluoride effects on IQ in children.

The literature on adults is also limited; therefore, it was determined that there is [underlined: low confidence] in the body of evidence from studies that evaluate fluoride exposure and adult cognition. Compared to the literature in adults, there is a much more extensive literature in children.

The literature in children was separated into studies assessing IQ and studies assessing other cognitive or neurodevelopmental outcomes. There is [underlined: low confidence] in the body of evidence from studies that evaluate fluoride exposure and other cognitive or neurodevelopmental outcomes in children. The confidence in this body of evidence is low because the number of studies is limited, and there is too much heterogeneity in the outcomes measured, ages assessed, and methods used to directly compare studies of any one outcome. This body of evidence is made up of nine high-quality studies (three prospective cohort and six cross-sectional studies from seven different study populations) and six low-quality studies. Eight of the nine high-quality studies observed significant associations between fluoride and other cognitive or neurodevelopmental outcomes in children including ADHD, visuospatial organization and memory, NBNA, MDI, GCI, and MSCA. The data also suggest that neurodevelopmental effects occur in very young children. Additional studies on outcomes such as ADHD and other attention-related disorders, where there is some evidence of an association with estimated fluoride exposure (i.e., all four studies evaluating attention-related disorders or learning disabilities found a statistically significant positive association between fluoride exposure assessment measure and measures of ADHD or learning disability), would be necessary to critically assess the data.

Most of the epidemiological studies (n = 72) assessed the association between estimated fluoride exposure and IQ in children. Although all studies, both high- and low-quality, were considered, this evaluation focuses on the high-quality, low risk-of-bias studies in children for two reasons. First, there are fewer limitations and greater confidence in the results of the high-quality studies. Second, there is a relatively large number of high-quality studies (n = 19), such that the body of evidence from these studies could be used to evaluate confidence in the association between fluoride exposure and changes in children’s IQ.

This review finds, with [underlined: moderate confidence], that higher estimated fluoride exposures (e.g., as in approximations of exposure such as drinking water fluoride concentrations that exceed the World Health Organization Guidelines for Drinking-water Quality of 1.5 mg/L of fluoride) are consistently associated with lower IQ in children. The inverse association between estimated fluoride exposure and IQ in children was consistent across different study populations, study locations, study quality/risk-of-bias determinations, study designs, exposure assessment measures, and types of exposure data (group-level and individual-level). There were 19 low risk-of-bias studies that were conducted in 15 study populations, across 5 countries, and evaluating more than 7,000 children. Of these 19 studies, 18 reported an inverse association between estimated fluoride exposure [e.g., as in approximations of fluoride exposure such as drinking water fluoride concentrations that exceeded the WHO Guidelines for Drinking-water Quality of 1.5mg/L of fluoride] and lower IQ. These include 3 prospective cohort studies and 15 cross-sectional studies (12 of which indicated that exposure likely preceded the outcome). Forty-six of 53 low-quality studies in children also reported an association between higher fluoride exposure assessment measures and lower IQ.

The moderate confidence rating was reached by starting with an initial confidence rating based on key study design features of the body of evidence and then considering factors that may increase or decrease the confidence in that body of evidence. The initial moderate confidence rating is based on 15 of the 19 low risk-of-bias studies that have 3 of the 4 key study design features shown in Figure 1 (i.e., exposure occurred prior to outcome, individual-based outcomes were evaluated, and a comparison group was used). Three of these studies were prospective cohort studies, and 12 were cross-sectional studies that provided evidence of long-term, chronic fluoride exposure prior to outcome measurement.

Many studies in this assessment relied on drinking-water fluoride levels (both group-level measures and individual-level measures), rather than measures of total fluoride exposure, to establish exposed versus “unexposed” or reference groups. Although fluoride in water is a major source of exposure [comprising 40% to 70% of total exposure (USEPA 2010)], other sources of fluoride provide variable amounts that depend on personal preferences and habits. The use of dental products containing fluoride and consuming foods and beverages prepared with fluoridated water can also result in measurable exposures (USEPA 2010). Green et al. (2019) suggested that significant exposures occur from black tea consumption. Thus, drinking water fluoride levels may, but usually do not, reflect total fluoride exposure. This could be a potential limitation in studies that rely on water fluoride data to assess fluoride exposure (in particular, earlier studies). Because water is only part of a person’s total exposure to fluoride, this limitation would likely result in an underestimate of exposure to fluoride. In other words, in studies where the exposure metric was drinking water fluoride concentrations that were lower than the WHO Drinking Water Quality Guideline of 1.5 mg/L for example, actual exposures may be underestimated due to exposures from other sources. This limitation is less of a concern in areas where fluoride in the drinking water is high because drinking water likely contributes a larger proportion of the total fluoride intake in those areas as compared with areas where fluoride in the drinking water is lower.

This review found that the quality of exposure assessment measures has improved over the years. More recent studies by Valdez Jiménez et al. (2017), Bashash et al. (2017), and Green et al. (2019) that support the inverse associations between estimated total fluoride exposure and children’s IQ and other cognitive neurodevelopmental effects, used individual measures of urinary fluoride, either maternal urine collected prenatally or children’s urine. Studies using different types of exposure assessment measures reported similar findings of an association (NRC 2006), which strengthens confidence in earlier studies that reported IQ deficits with high group-level fluoride exposure. However, there is less certainty in the quantitative estimates of the magnitude of IQ deficits from earlier studies that used group-level exposure assessment measures than the estimates from more recent studies that used individual-level exposure assessment measures.

It is worth noting that there are circumstances wherein typical children’s water consumption considered with water fluoride levels may substantially underestimate total fluoride exposure. One example is bottle-fed infants wherein nutrition is provided by powdered formula that is rehydrated with fluoridated water (Till et al. 2020). To decrease an exclusively formula-fed infant’s exposure to fluoride, for the purpose of reducing risk of dental fluorosis, the Centers for Disease Control and Prevention recommends using low-fluoride bottled water to mix with infant formula (CDC 2015). A few studies also support the hypothesis that individuals with certain genetic variants in dopamine receptor D2 or catechol-O-methyltransferase may be at heightened sensitivities to the potential detrimental cognitive effects of fluoride exposure (Cui et al. 2018; Zhang et al. 2015b), potentially impacting dopamine catabolism and receptor sensitivity. Given the growing body of evidence suggesting an inverse association between estimated total fluoride intake and certain neurodevelopmental effects in children, differential exposures to total fluoride intake and genetic susceptibilities of children to fluoride may represent special situations that would appear to warrant further research.

The following section briefly recaps the strength of the epidemiological evidence for an association between fluoride exposure and cognitive neurodevelopmental deficits. This is followed by a more detailed listing of limitations of the evidence base and limitations of the systematic review, with some suggestions of areas where further research may be most beneficial.

## Limitations of the Evidence Base

Limitations in the epidemiological studies with low risk of bias include:

- Few studies are available that assessed the association between fluoride exposure and cognitive function (particularly IQ) in adults and attention-related disorders including ADHD in children and adults.
- Heterogeneity in outcomes was assessed for other neurobehavioral outcomes, limiting the assessment of other possible effects in children.
- Studies rarely separated the results by sex or provided information to indicate that sex was not a modifying factor.
- Associations between lower estimated total fluoride exposure [e.g., as in approximations of exposure such as drinking water fluoride concentrations that were lower than the WHO Guidelines for Drinking-water Quality of 1.5 mg/L of fluoride (WHO 2017)] and children’s IQ remain unclear. More studies estimating lower exposure levels are needed to fully understand potential associations in ranges typically found in the United States (i.e., <1.5 mg/L in water). However, it should be noted that, as of April 2020, CWS supplying water with ≥1.5 mg/L naturally occurring fluoride served 0.59% of the U.S. population (~1.9 million people) (CDC Division of Oral Health 2020). This indicates that the moderate confidence in the association between higher fluoride exposure and lower IQ is relevant, at a minimum to children living in these areas of the United States where fluoride in drinking water is known to be at or above 1.5 mg/L. This is only compounded by additional exposures to fluoride from other sources.
- No high-quality studies investigating the association between fluoride exposure and neurodevelopmental or cognitive effects in adults or children have been conducted in the United States.
- No studies are available to evaluate lifelong exposure in adults or fluoride exposure over a child’s lifetime and neurodevelopmental or cognitive changes over time.
- Biomarkers that reflect total fluoride exposure are exposure estimates and not a measure of actual exposure. Although we have noted above why spot urine samples are considered low potential for bias, they do represent recent exposure and can vary. Although human serum levels tend to reflect fluoride levels in water (IPCS 2002), they vary widely during the day, and only rarely were they measured or reported in the literature that was evaluated.
- The database does not allow for comparison of ages and possible changes at different developmental stages in children to assess if there is a delay in development or if associations persist.
- The database does not allow for establishing clear correlations between prenatal and postnatal exposures.

Limitations in the epidemiological studies with high risk of bias include:

- Many of the original publications were in a non-English language and provided limited details on methodology.
- Most studies lacked information regarding exposure and/or had serious limitations in the exposure assessment measures. Exposure assessment measure concerns include limited individual exposure information, a lack of information on fluoride sampling methods and timing of the exposure assessment measurements, a lack of quantitation of levels of fluoride in drinking water in a few studies, and a lack of individual-level information on fluorosis in areas reported to be endemic for fluorosis.
- The comparison groups in studies conducted in areas endemic for fluorosis still may have been exposed to high levels of fluoride or levels similar to those used in water fluoridation in the United States. This factor may have limited the ability to detect true effects.
- Many studies did not provide sufficient direct information (e.g., participation rates or methods for selection) to evaluate selection bias.
- Failure to address important covariates was an issue for most of the studies. Some studies conducted simple statistical analyses without accounting for any covariates in the analysis, although many noted similarities between the study populations. In cases where adjustments in analyses were made, often these studies did not account for covariates considered critical for that study population and outcome including co-exposures.
- Studies conducted in areas with high, naturally occurring fluoride levels in drinking water often did not account for potential exposures to arsenic or iodine deficiencies in study subjects in areas where these substances were likely to occur.
- Many studies lacked information on whether the outcome assessors were blind to the exposure group, including studies that examined children in their schools and subjects from high-fluoride communities.

Limitations in the animal and mechanistic evidence base include:

- The overall quality of the experimental animal studies is poor, and there are relatively few well-designed and well-performed studies at lower fluoride exposure levels (i.e., <20 ppm, which is roughly equivalent to human exposure of <4 ppm).
- The understanding of the specific molecular events responsible for fluoride’s adverse effects on neurobehavioral function is poor.

A key data gap in the human and animal bodies of evidence includes the need for mechanistic insight into fluoride-related neurodevelopmental or cognitive changes.

## Limitations of the Systematic Review

This systematic review has relatively few limitations. The human body of evidence included a large database of observational studies. Most of the observational studies were cross-sectional; however, 12 of these were considered to provide sufficient evidence that exposure occurred prior to the outcome. In addition, the systematic review covered a wide range of study designs, populations, and measures of fluoride exposure. The systematic review was designed to cover reports on all potential mechanistic data including effects on the thyroid. After review of the studies evaluating thyroid effects, studies that only evaluated goiters and other effects on thyroid size were not considered in this review. This is not considered a limitation because these studies did not include specific information on thyroid hormones that could indicate a mechanism for thyroid involvement in neurodevelopment. In addition, review of the mechanistic data was limited to in vivo studies with at least one concentration below 20 ppm. This is not considered a limitation for the systematic review because the mechanistic body of evidence was used to evaluate biological plausibility for the effects observed in humans; therefore, data were limited to concentrations that would be more reflective of human exposures. The decision to not more closely evaluate the in vitro data is not considered a limitation because there were sufficient in vivo data, and no key events were identified where in vitro data would provide additional insight.

The supplemental literature search for non-English-language studies not indexed in traditional databases supports the comprehensive nature of the literature search strategy for this systematic review. In the absence of guidance on the most complete non-English-language databases that may contain health studies of fluoride, a standard systematic review approach for database selection was followed whereby a set of exemplar documents, called ‘seed studies’, were used. Databases were selected that identified non-English-language studies of fluoride that we were aware of and were not captured in searches of databases from the main literature search. This informed approach influenced the selection process; however, this is not considered a limitation because it provided an objective measure by which to compare databases. Following the recommendation of the NASEM committee in its review of the September 16, 2020, draft monograph, the experimental animal section has been removed and is not included in this monograph. Although the deficiencies identified in the animal body of evidence support this removal (see Animal Learning and Memory Data for further explanation), NTP acknowledges that the absence of the experimental animal data is a limitation of this systematic review. For the purpose of this review, NTP considers the experimental animal data to be inadequate to inform whether fluoride exposure is associated with cognitive effects (including cognitive neurodevelopmental effects) in humans.