# Appendix H Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-MGRAPH-8 (NTP 2024).

## H.1 Protocol

NTP Protocol for Systematic Review of Human, Animal, and Mechanistic Evidence - Second Revision (September 16, 2020)

NTP Protocol for Systematic Review of Human, Animal, and Mechanistic Evidence - First Revision (May 29, 2019)

NTP Protocol for Systematic Review of Human, Animal, and Mechanistic Evidence (June 2017)

## H.2 Datasets

Interactive Reference Flow Diagram (NTP Monograph Figure 2)

Interactive Reference Flow Diagram for Updated Literature Search (NTP Monograph Addendum Figure 1)

NTP Monograph Interactive Figure 3

NTP Monograph Interactive Figures 7 and 8

NTP Monograph Interactive Figure F-1

NTP Monograph Interactive Figure F-2