# Appendix G Protocol History and Revisions

Table G-1 Protocol History and Revisions

Date | Activity or Revision
December 14, 2016 | Draft evaluation protocol reviewed: sent to technical advisors for peer review
April 10, 2017 | Draft human risk-of-bias protocol reviewed: sent to technical advisors for peer review
May 2, 2017 | Draft animal risk-of-bias protocol reviewed: sent to technical advisors for peer review
June 2017 | Evaluation protocol finalized: Review protocol finalized for use and posting
May 29, 2019 | Revised protocol: Revised review protocol posted
September 16, 2020 | Revised protocol: Revised review protocol posted