# Appendix E Details for Low Risk-of-bias Studies

## E.1 IQ Studies

### E.1.1 Bashash et al. (2017)

#### E.1.1.1 Study Details

- Study design: Prospective cohort
- Population: Early Life Exposures in Mexico to Environmental Toxicants (ELEMENT) participants (pregnant mothers and their children aged 4 or 6–12 years).
- Study area: Mexico City, Mexico
- Sample size: 299 mother-child pairs, of whom 211 had data for the IQ analyses and 287 had data for the general cognitive index (GCI).
- Data relevant to the review: Adjusted and unadjusted associations between IQ scores and maternal or child’s urinary fluoride concentrations.
- Reported association with fluoride exposure: Yes: Significant inverse association between maternal urinary fluoride and IQ score (adjusted β = −2.50 per 0.5-mg/L increase; 95% CI: −4.12, −0.59). Significant inverse association between maternal urinary fluoride and GCI score (adjusted β per 0.5 mg/L increase = −3.15; 95% CI: −5.42, −0.87). No significant associations with children’s urinary fluoride.

#### E.1.1.2 Risk of Bias

- Author contacts:
  - Authors were contacted for additional information on whether clustering was addressed. The authors provided results from additional models with cohort as a random effect, which informed the rating decision for the following risk-of-bias domains: Other.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Study participants were selected from two different cohorts from three hospitals in Mexico City that serve low-to-moderate income populations. One cohort was from an observational study of prenatal lead exposure and neurodevelopment outcomes, and the other was from a randomized trial of the effect of calcium on maternal blood lead levels. The authors state that participants had no history of psychiatric disorders, high-risk pregnancies, gestational diabetes, illegal drug use, or continuous prescription drugs, but no information on smoking habits was considered. Study populations appear to be similar, but there may be some differences because subjects were selected from two different cohorts that were recruited from slightly different time periods.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar despite the subjects coming from different original study populations wherein different methods were used for recruitment.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Data were collected via questionnaire on maternal age, education, marital status at first prenatal visit, birth order, birth weight, gestational age at delivery, maternal smoking, maternal IQ, and HOME scores. All models were adjusted for gestational age at birth, sex, birth weight, birth order, age at testing, maternal marital status, smoking history, age at delivery, maternal IQ, education, and cohort, with additional testing for children’s urinary fluoride, mercury, lead, and calcium. Sensitivity analyses additionally adjusted for HOME score. Important covariates not considered included BMI, iodine deficiency, arsenic, and maternal mental health and nutrition. Arsenic is assumed not to be a potential co-exposure in this population because the study authors did not discuss it as an issue, although other co-exposures were considered. Arsenic is included in the water quality control program in Mexico City and is thus not considered a concern in this population.
  - [underlined: Potentially important study-specific covariates]: All key covariates were addressed.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that key covariates, including other potential co-exposures, were addressed and indirect evidence that the methods used to collect the information were valid and reliable and that arsenic is not likely to be an issue in this study population.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Although there was a large amount of attrition, the study authors clearly describe all reasons for attrition and also provide characteristics to compare those participants included to those excluded. There were some slight differences between those included and those excluded, but there is no evidence to indicate that the attrition would potentially bias the results.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Urinary fluoride concentrations were determined in spot urine samples (second morning void) collected from mothers (during at least one trimester) and children ages 6–12 years. Fluoride content was measured using ion-selective electrode-based assays. Quality control methods were described, including between-laboratory correlations. All samples were measured in duplicate. Extreme outliers were excluded. Urinary dilution was addressed by using creatinine-adjusted levels.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Outcome was assessed using the McCarthy Scales of Children’s Abilities (MSCA) in 4-year-old children (translated into Spanish) and the Wechsler Abbreviated Scale of Intelligence (WASI) in 6–12-year-olds. The WASI is a well-established test, and the validity of both tests is well documented by the authors. Inter-examiner reliability was evaluated and reported with a correlation of 0.99 (++ for methods). The study report stated that psychologists were blind to the children’s fluoride exposure (++ for blinding). Overall rating for methods and blinding = ++.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses used were appropriate for the study. Statistical tests of bivariate associations (using Chi-square tests for categorical variables and analysis of variance [ANOVA]) were used to compare the means of the outcomes or exposure within groups based on the distribution of each covariate. Generalized additive models (GAMs) were used to estimate the adjusted association between fluoride exposure and measures of children’s intelligence. Residual diagnostics were used to examine model assumptions and identify any potentially influential observations. Results are reported as adjusted regression slopes and 95% CIs. In sensitivity analyses, regression models accounted for clustering at the cohort level by using cohort as a fixed effect in the models. Although using cohort as a random effect would be more appropriate, using individual-level exposure data and accounting for numerous important covariates in the models likely captured the cohort effect. Additional models with cohort as a random effect were also subsequently made available via personal communication with the study authors and showed similar results to the main model.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Definitely low risk if bias is based on direct evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements, blinding of outcome assessor to participants’ fluoride exposure, and the prospective cohort study design.

### E.1.2 Choi et al. (2015)

#### E.1.2.1 Study Details

- Study design: Cross-sectional
- Population: First-grade children (ages 6–8 years)
- Study area: Mianning County in southern Sichuan, China
- Sample size: 51 first-grade children
- Data relevant to the review: Associations between urinary or drinking water fluoride levels and IQ measures (digit span for auditory span and working memory and block design for visual organization and reasoning components of WISC-IV only). Study also had information based on dental fluorosis score.
- Reported association with fluoride exposure: Yes: Significant association between dental fluorosis and digit span scores. Compared to the normal/questionable dental fluorosis, the moderate/severe dental fluorosis group was associated with significantly lower total (adjusted β = −4.28; 95% CI: −8.22, −0.33) and backward (adjusted β = −2.13; 95% CI: −4.24, −0.02) digit span scores. No associations between urinary fluoride and total digit span and log-transformed fluoride in urine (adjusted β = −1.67; 95% CI: −5.46, 2.12) and between drinking water and total digit span (adjusted β = −1.39; 95% CI: −6.76, 3.98). Other outcomes were not significantly associated with fluoride exposure.

#### E.1.2.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Subjects were selected during the same time frame using the same methods. Fifty-one first-grade children residing in Mianning County in southern Sichuan, China were included in this pilot study. It is not specified whether the 51 children represented all the first-grade children from this area or whether some refused to participate. Children who did not speak Chinese, were not students at the Primary School of Sunshui Village in Mianning County, or those with chronic or acute disease that might affect neurobehavioral function tests were excluded. Demographic characteristics are presented in Table 1 of the study, which indicates that subjects were similar. Important covariates are adjusted for in the statistical analyses.
  - [underlined: Basis for Rating]: Definitely low risk of bias based on direct evidence that the exposure groups were similar and were recruited within the same time frame using the same methods with no evidence of differences in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The parents or guardians completed a questionnaire on demographic and personal characteristics of the children (sex, age at testing, parity, illnesses before age 3, and past medical history) and caretakers (age, parity, education and occupational histories, residential history, and household income). A 20-μL capillary blood sample was collected at the school by a Mianning County Center for Disease Control (CDC) health practitioner and tested for possible iron deficiency, which could have been used as a covariate of neurodevelopmental performance. Important covariates that were not assessed include maternal BMI, parental mental health, maternal smoking status, maternal reproductive factors, parental IQ, and HOME score. However, the study authors noted that confounding bias appeared to be limited due to the minimal diversity in the social characteristics of the subjects. The study authors indicated that CDC records documented that levels of other contaminants, including arsenic and lead, were very low in the area. Iodine differences were not specifically addressed, but there is no indication from the information provided that this might have been a concern.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias because there is direct evidence that the key covariates were considered and indirect evidence that co-exposure to arsenic was likely not an issue in this area and that methods used for collecting the information were valid and reliable.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The majority of results were reported for the 51 children stated to be included in the pilot study. In Table 5 of the study, the N for each dental fluorosis category totals only 43, but the text indicates 8 children did not have a Dean Index because permanent teeth had not erupted.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study used three different measurements of fluoride exposure: well water fluoride concentrations from the residence during pregnancy and onwards, fluoride concentrations from children’s first morning urine samples, and degree of children’s dental fluorosis. Fluoride concentrations in community well water were measured and recorded by Mianning County CDC; specific analytic methods were not reported, but it is likely that standard methods were used because the analyses were conducted by the CDC and were likely the same as those used to measure the fluoride in urine. Migration of subjects was noted to be limited. Well water fluoride concentrations of the mother’s residence during pregnancy and onward were used to characterize a child’s lifetime exposure. To provide a measure of the accumulated body burden, each child was given a 330-mL (11.2-oz) bottle of Robust© distilled water (free from fluoride and other contaminants) to drink the night before the clinical examinations, after emptying the bladder and before bedtime. The first urine sample the following morning was collected at home, and the fluoride concentration was determined on a 5-mL sample using an ion-specific electrode at the Mianning CDC. There is no indication that urinary fluoride levels accounted for dilution, nor was it clear that the method of administering water to the children and collection methods sufficiently controlled for differences in dilution. One of the investigators, a dentist, performed a blinded dental examination on each child’s permanent teeth to rate the degree of dental fluorosis using the Dean Index. The Dean Index is a commonly used index in epidemiological studies and remains the gold standard in the dentistry armamentarium. The Index has the following classifications: normal, questionable, very mild, mild, moderate, and severe. Quality control (QC) procedures are not reported but were likely appropriate.
    - Direction/magnitude of effect size: Current levels were used to assess lifetime exposure. This is likely to be a non-differential exposure misclassification, and direction of bias is unknown. Because subject migration appears to be limited, it is likely that the current fluoride levels are adequate reflections of past exposure. Dental fluorosis would be an indicator that exposure occurred in the past, and there was a fair correlation between degree of dental fluorosis and current urine and water fluoride levels, with both increasing with increasing levels of dental fluorosis.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measure exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study authors adopted culture-independent tests considered feasible for children aged 6 to 8 years. The Wide Range Assessment of Memory and Learning (WRAML) was used for the assessment of memory and learning. Three subtests were also used. The Finger Windows subtest assesses sequential visual memory. The Design Memory subtest assesses the ability to reproduce designs from memory following a brief exposure. The Visual Learning subtest assesses the ability to learn the locations of pictured objects over repeated exposures. The Wechsler Intelligence Scale for Children-Revised (WISC-IV) includes digit span for auditory span and working memory and block design for visual organization and reasoning. The grooved pegboard test assesses manual dexterity. The tests used have been validated on a Western population. Although there is no information provided to indicate that the tests were validated on the study population, the study authors indicated that the tests were culture-independent (+ for methods). Blinding of the outcome assessors to participants’ fluoride exposure, or steps to minimize potential bias were not reported. However, it is unlikely that the assessors had knowledge of the individual exposure as children all came from the same area, and water and urine levels were tested at the CDC. (+ for blinding). Overall = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that all outcomes were assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses are appropriate. Multiple regression models evaluate the associations between exposure indicators and test scores after adjusting for covariates. Specific regression models are not described or refenced, just stated to be “standard regression analysis with confounder adjustment.” The distributions of fluoride concentrations in urine and water are skewed and log10-transformed to approximate a Gaussian distribution (test not specified). Results are reported as adjusted regression slopes and 95% CIs. There is no evidence that residual diagnostics were used to examine model assumptions; however, the impact on the effect estimates is expected to be minimal.
    - Other potential concerns: It should be noted that this study was a pilot study and, therefore, had a relatively small sample size (i.e., 51 children).
  - [underlined: Basis for rating]: Probably low risk if bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in the confounding, exposure, and outcome domains. Study strengths include individual fluoride measurements with blinding at outcome assessment likely. All key covariates and many other important covariates were considered in the study design or analysis.

### E.1.3 Cui et al. (2018)

#### E.1.3.1 Study Details

- Study design: Cross-sectional
- Population: School children aged 7–12 years from four schools in two districts in China with different fluoride levels
- Study area: Jinghai and Dagang in Tianjin City, China
- Sample size: 323 school children
- Data relevant to the review: IQ scores by urine fluoride levels.
- Reported association with fluoride exposure: Yes: Significant inverse association between urinary fluoride and IQ score (adjusted β = −2.47 per 1-log-mg/L increase; 95% CI: −4.93, −0.01).

#### E.1.3.2 Risk of Bias

- Author contacts:
  - Authors were contacted in June 2019 to obtain additional information for risk-of-bias evaluation. Additional information provided by the authors informed the rating decision for the following risk-of-bias domains: Detection (outcome assessment).
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Four schools were selected from the same district in China. The schools were selected based on levels of fluoride in the local drinking water and the degree of school cooperation. No details were provided on the number of schools in given areas or the difficulty in getting school cooperation. It was noted that the residents in the four areas had similar living habits, economic situations, and educational standards. Although authors do not provide the specific data to support this, fluoride levels and IQ scores were provided by different subject characteristics. The areas were classified as historically endemic fluorosis and non-fluorosis. Cluster sampling was used to select the grades in each school according to previously set child ages, and classroom was randomly selected with all students within a selected classroom included. Reasons for exclusion do not appear to be related to exposure or outcome.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and recruited within the same time frame using the same methods, with no evidence of differences in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The measurements of all covariates were obtained by structured questionnaires that were completed by children with the help of their parents. Covariates that were assessed include: sex, age, child’s ethnicity, child’s BMI, birth (normal vs. abnormal), mother’s age at delivery, mother’s education, income per family member, mother’s smoking/alcohol during pregnancy, family member smoking, environmental noise, iodine region (non-endemic vs. iodine-excess-endemic area), factory within 30 m of residence, iodine salt, diet supplements, seafood/pickled food/tea consumption, surface water consumption, physical activity, stress, anger, anxiety/depression, trauma, having a cold 5 times a year, thyroid disease in relatives, mental retardation in relatives, and cancer in relatives. Covariates not considered include parity, maternal and paternal IQ, and quantity and quality of caregiving environment (e.g., HOME score). The authors report that there were no other environmentally toxic substances that might have affected intelligence, such as high arsenic or iodine deficiency according to the Tianjin Centers for Disease Prevention and Control.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias because there is indirect evidence that the key covariates were considered, methods for collecting the information were valid and reliable, and co-exposure to arsenic was likely not an issue in this area.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Of the 400 children enrolled, 35 were excluded because they did not have informed consent signed by a guardian or they moved out of the area. Forty-two children were excluded because they did not have a DRD2 genotyping measurement. It is unclear whether these children were from the same schools or whether they were evenly distributed throughout the study area. It is also unclear whether the excluded subjects were similar to those included in the study. In the study, some analyses had fewer than the 323 subjects, but this seems reasonable given the subgroups that were being evaluated.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Although children were selected based on area fluoride levels, fluoride in the urine was used in the analysis. Urine was collected from each child during the morning of enrollment and analyzed within a week. Fluoride levels were measured using an ion-selective electrode according to the China standard. A brief description of the method was provided, but no QC methods were reported. The study authors did not account for urinary dilution in the spot samples.
    - Direction/magnitude of effect size: Not accounting for dilution could cause some exposure misclassification. The direction and magnitude would depend on where the differences occurred.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using acceptable methods that provide individual levels of exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: IQ was measured by professionals using the Combined Raven’s Test–The Rural in China method, which is the appropriate test for the study population (++ for methods). Blinding or other methods to reduce bias were not reported. Although it was unlikely that the outcome assessor would have knowledge of the child’s urine fluoride levels, there was potential that they would know whether the child was from an endemic or non-endemic area if the IQ tests were conducted at the child’s school, and there was no information provided on how the IQ tests were administered. Correspondence with the study author noted the cross-sectional nature of the study with outcome and exposure assessed at the same time, making the outcome assessors blind to the exposure status of participants. However, there was still potential for knowledge of the area (+ for blinding).
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses were appropriate. Multiple linear regression models were applied to evaluate the relationship between urine fluoride levels and IQ scores, accounting for numerous important covariates. The urinary fluoride levels were log-transformed due to a skewed distribution. Residual diagnostics were used to examine model assumptions. Model robustness was tested through bootstrap, sensitivity analysis after excluding potential outliers, and cross-validation techniques. Results are reported as adjusted regression slopes and 95% CIs. The analysis did not account for clustering at the school level or at the grade level (students were from four schools in grades selected via a clustered sampling method). There is no evidence that the sampling strategy was otherwise accounted for via sampling weights. The impact of these factors on the effect estimates is expected to be minimal given the use of individual-level data and adjustment for several important covariates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate, and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements but are limited by the cross-sectional study design and lack of accounting for urine dilution. All key covariates were considered in the study design or analysis.

### E.1.4 Cui et al. (2020)

#### E.1.4.1 Study Details

- Study design: Cross-sectional
- Population: School children aged 7–12 years
- Study area: Tianjin City, China (one randomly selected school from each district based on iodine levels in the water), presumably was an expansion of the Cui et al. (2018) study
- Sample size: 498 school children
- Data relevant to the review: Mean IQ scores by urine fluoride levels.
- Reported association with fluoride exposure: Yes: A 2-point decrease in IQ was observed in the highest urinary fluoride group compared to the lowest urinary fluoride group (i.e., 110.00 in ≥2.5-mg/L group versus 112.16 in <1.6-mg/L group); however, the results did not achieve statistical significance based on a one-way ANOVA comparing the three different urinary fluoride categories only.

#### E.1.4.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for the 2020 publication. Authors were contacted in June 2019 for additional information on the Cui et al. (2018) publication. Additional information provided by the authors regarding Cui et al. (2018) informed the rating decision for the following risk-of-bias domains: Detection (outcome assessment).
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were recruited from 2014 to 2018. One school was selected from each district where water concentrations of water iodine were <10, 10–100, 100–150, 150–300 and >300 µg/L. In each school, classes were randomly sampled for the appropriate age group of 7–12 years old. A table of subject characteristics was provided by IQ. A total of 620 children were recruited, and 122 children who did not have complete information or enough blood sample were excluded. Reasons for exclusion do not appear to be related to exposure or outcome. The characteristics of the 498 included children are presented.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited within the same time frame using the same methods, with no evidence of differences in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: It was noted by the study authors that there were no other environmental poisons except water fluoride. Other studies also conducted in this area of China noted specifically that arsenic was not a concern. Iodine was addressed as that was one of the main points of the study. Twenty-one factors (provided in Table 1 of the study) were selected as covariates, and a homemade questionnaire of unspecified validity was used for obtaining the information. It was noted that child age, stress, and anger were significantly associated with IQ although it is unclear whether these varied by fluoride level. However, Cui et al. (2018) indicate that fluoride was not significantly associated with stress and anger, and it was assumed that results would be similar for this study even though more children were included.
  - [underlined: Potentially important study-specific covariates]: Age (children 7–12 years old)
    - Direction/magnitude of effect size: Age is a key covariate for IQ, even in the narrow age range evaluated in this study. The direction of the association may depend on the number of children in each age group within the different urinary fluoride categories; however, these data were not provided. In general, there were fewer subjects ≤9 years of age (i.e., 111) compared to >9 years of age (i.e., 387) with a significantly higher IQ in the ≤9-year-old age group. Therefore, if exposure were higher in the older subjects, this could likely bias the association away from the null.
  - [underlined: Basis for rating]: Probably high risk of bias because there is indirect evidence that age was not addressed as a key covariate, and it may be related to both IQ and exposure.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Of the 620 children recruited, 122 (20%) were excluded due to incomplete information or inadequate blood sample. No information was provided to indicate whether there were similarities or differences in the children included versus the children excluded, but exclusion is unlikely to be related to either outcome or exposure.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Children’s morning urine was collected with a clean polyethylene tube, and fluoride was measured using a fluoride ion-selective electrode following Chinese standard WS/T 89-2015. A brief description was provided, but no QC methods were reported. The study authors do not account for urinary dilution in the spot samples.
    - Direction/magnitude of effect size: Not accounting for dilution could cause some exposure misclassification. The direction and magnitude would depend on where the differences occurred.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using acceptable methods that provide individual levels of exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: IQ was measured using the Combined Raven’s Test, which is an appropriate test for the study population (++ for methods). Blinding was not mentioned; however, the outcome assessors would not likely have had knowledge of the child’s urinary fluoride. Subjects appear to have been recruited based on iodine levels; therefore, it is unlikely that there would have been any knowledge of potential fluoride exposure. Correspondence with the study authors for the Cui et al. (2018) study also indicated that the outcome assessors would have been blind.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: One-way ANOVA was used to make comparisons between mean IQ by urinary fluoride levels. Consideration of heterogeneity of variances was not reported. There is no adjustment for covariates or for clustering of children at the school level. There is no evidence that the sampling strategy was otherwise accounted for (i.e., via sampling weights). The impact of these factors on the effect estimates is expected to be minimal given the use of individual-level data. The primary focus of the study was to evaluate associations between IQ and thyroid hormone or dopamine levels (not between IQ and fluoride levels). It should also be noted that more advanced analyses used for thyroid hormone- and dopamine-IQ associations still lacked adjustment for school and accounting for clustering of children from the same school.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate, and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in exposure and outcome. Study strengths include individual exposure assessment measurements, but the study is limited by the cross-sectional study design, lack of accounting for urine dilution, and lack of addressing age as a key covariate.

### E.1.5 Ding et al. (2011)

#### E.1.5.1 Study Details

- Study design: Cross-sectional
- Population: Elementary school children aged 7–14 years old
- Study area: Hulunbuir City, Inner Mongolia, China
- Sample size: 331 school children
- Data relevant to the review: IQ mean difference based on 10 categories of urine fluoride. Adjusted associations between urinary fluoride and IQ scores.
- Reported association with fluoride exposure: Yes: Significant inverse association between urinary fluoride and IQ score (adjusted β = −0.59 per 1-mg/L increase; 95% CI: −1.09, −0.08).

#### E.1.5.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study randomly selected 7–14-year-olds (n = 340) from four nearby elementary schools in Hulunbuir. The four elementary schools appeared to be very similar in teaching quality. The study authors noted that they followed the principles of matching social and natural factors like economic situation, educational standards, and geological environments as much as possible; however, how this was done is unclear and no table of study subject characteristics by group was provided.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited within the same time frame using the same methods, with no evidence of differences in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: It was noted that none of the four sites had other potential neurotoxins, including arsenic, in their drinking water. Details were not provided, except for a reference supporting the statement. In addition, iodine deficiency was noted as not being an issue in any of the four areas. Age was the only key covariate adjusted for in the regression model. Although dental fluorosis severity by % female was reported, not enough data were provided to determine whether sex should have been considered in the regression model. The study authors note that future studies will include covariates such as parents’ educational attainment, mother’s age at delivery, and household income.
  - [underlined: Potentially important study-specific covariates]: Sex
    - Direction/magnitude of effect size: There is not enough information to determine whether there was an effect from sex. There were some differences in dental fluorosis level by sex, but it is unclear how this might impact the results or whether the distribution of sex differed by age.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that there were differences in sex that were not considered in the study design or analyses.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Data were relatively complete (i.e., <5% loss). Of the 340 subjects selected for inclusion, 5 were excluded because they lived in the area for less than a year with an additional 4 not consenting to participate.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exclusion of subjects from analysis was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Spot urine samples were collected and measured using China CDC standards. All samples were analyzed twice using a fluoride ion-selective electrode. Recovery rates were specified as 95%–105% with an LOD of 0.05 mg/L. Water samples were collected from small-scale central water supply systems and tube wells with handy pumps and were processed using standard methods, similar to the urine samples. Quality assurance validation was reported. A blind professional examiner evaluated the children for dental fluorosis using Dean’s Index. All urine and water samples were above the LOD. Urine levels were the primary exposure assessment measures used in the analysis. The study authors did not account for urinary dilution in the spot samples. The mean urine fluoride concentration was correlated with the dental fluorosis levels.
    - Direction/magnitude of effect size: Spot urine samples that did not account for dilution could have exposure misclassification. The misclassification is likely non-differential, and the potential direction of bias is unknown.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measure exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: IQ was determined using the Combined Raven’s Test–The Rural in China (CRT-RC3) (++ for methods). Although blinding was not reported, it is unlikely that the IQ assessors had knowledge of the children’s urine levels or even of the water levels from the four sites, as these were sent to a separate lab for testing (+ for blinding). Overall rating for methods and blinding = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses were reasonable (ANOVA and multiple linear regression), but consideration of homogeneity of variance was not reported. The NASEM committee’s review (NASEM 2021) pointed out a potential concern regarding the lack of accounting for clustering at the school level because children were selected from four elementary schools. However, as outlined in the Selection domain, the authors stated that they followed the principles of matching social and natural factors like economic situation, educational standards, and geological environments to the extent possible and that the four elementary schools appeared to be very similar in teaching quality. There is no evidence that the sampling strategy was otherwise accounted for (i.e., via sampling weights). The impact of these factors on the effect estimates is expected to be minimal given the use of individual-level data and adjustment for age as a key [underlined: covariate].
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and that there were no other potential threats of risk of bias.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in exposure and outcome. Study strengths include individual exposure assessment measurements, but the study is limited by the cross-sectional study design, lack of accounting for urine dilution, and lack of consideration of sex as a key [underlined: covariate].

### E.1.6 Green et al. (2019)

#### E.1.6.1 Study Details

- Study design: Prospective cohort
- Population: Maternal-Infant Research on Environmental Chemicals (MIREC) participants (pregnant mothers and their children aged 3–4 years)
- Study area: 10 cities, Canada
- Sample size: 512 mother-child pairs (238 from non-fluoridated areas, 162 from fluoridated areas; 264 females, 248 males)
- Data relevant to the review: Adjusted associations between maternal urinary fluoride across all three trimesters, estimated maternal fluoride intake, or drinking water fluoride and IQ.
- Reported association with fluoride exposure: Yes: Significant inverse association between maternal urinary fluoride and IQ in boys (adjusted β = −4.49 per 1-mg/L increase). No significant associations in girls or in both sexes combined. Significant inverse associations between maternal intake and IQ in both sexes combined (adjusted β = −3.66 per 1-mg/day increase; 95% CI: −7.16, −0.15). Significant inverse associations between drinking water fluoride and IQ in both sexes combined (adjusted β = −5.29 per 1-mg/L increase; 95% CI: −10.39, −0.19). No significant effect modification by sex for maternal fluoride intake and drinking water fluoride associations.

#### E.1.6.2 Risk of Bias

- Author contacts:
  - Authors were contacted in June 2019 for additional information for the risk-of-bias evaluation. Additional information provided by the authors informed the rating decision for the following risk-of-bias domains: Other.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Pregnant women were recruited from the same population during the same time frame and using the same methods as the MIREC program. Methods were reported in detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposed groups were similar and were recruited with the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study considered several possible covariates, including maternal age, pre-pregnancy BMI, marriage status, birth country, race, maternal education, employment, income, HOME score, smoking during pregnancy, secondhand smoke in the home, alcohol consumption during pregnancy, parity, sex, age at testing, gestational age, birth weight, time of void, and time since last void. The study also conducted secondary analyses to test for lead, mercury, arsenic, and PFOA. There is no indication of any other potential co-exposures in this study population. Iodine deficiency or excess could not be assessed but is not expected to differentially occur. The study was not able to assess parental IQ or mental health disorders. Methods used to obtain the information included questionnaires and laboratory tests.
  - [underlined: Potentially important study-specific covariates]: All key covariates were addressed.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the methods used to collect the information were valid and reliable and direct evidence that key covariates, including potential co-exposures, were addressed.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Of the 610 recruited children, 601 (98.5%) completed testing. Of the 601 mother-child pairs, 512 (85.2%) had all three maternal urine samples and complete covariate data, and 400 (66.6%) had data available to estimate fluoride intake.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Spot urine samples from all three trimesters of pregnancy were evaluated using appropriate methods, and results were adjusted for creatinine and specific gravity. Fluoride intake was estimated based on fluoride water levels, and information on consumption of tap water and other water-based beverages (e.g., tea, coffee) was obtained via questionnaire.
    - Direction/magnitude of effect size: There is not any specific direction or magnitude of bias expected. Urinary fluoride levels are reflective of a recent exposure. Having measurements from all three trimesters of pregnancy provides a better representation of actual exposure than a single measurement, although the potential for missed high exposure is possible. However, the possibility of the occurrence of missed high exposure would be similar in all females and would be non-differential. For the fluoride intake, exposure was based on the fluoride levels in the water at the residence. If women worked outside the home and the majority of intake occurred from areas outside the home (and were different from levels in the home), there is potential to bias toward the null.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The Wechsler Preschool and Primary Scale of Intelligence was normalized for ages 2.5–<4.0 and sex using the U.S population-based norms. Blinding was not reported, but it is unlikely that the outcome assessors had knowledge of the maternal fluoride level or were aware of whether the city had fluoridated water.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes were reported.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]:
    - Statistical analyses: Multivariate linear regression analyses were used to evaluate the associations between maternal urinary fluoride and fluoride intake and children’s IQ scores. Regression diagnostics were used to test assumptions for linearity, normality, and homogeneity. There were no potential influential observations (based on Cook’s distance). Sensitivity analyses showed that the effects of maternal urinary fluoride (MUF), fluoride intake, and water fluoride were robust to the exclusion of two very low IQ scores in males (<70). City was accounted for as a covariate in the regression models published. Additional models with city as a random effect were also subsequently made publicly available and showed similar results to the main model.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements, prospective cohort design, and the consideration of key covariates.

### E.1.7 Rocha-Amador et al. (2007)

#### E.1.7.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 6–10 years
- Study area: Moctezuma (low fluoride, low arsenic) and Salitral (high fluoride, high arsenic) of San Luis Potosí State and 5 de Febrero (high fluoride, high arsenic) of Durango State, Mexico
- Sample size: 132 children
- Data relevant to the review: Adjusted associations between urinary or drinking water fluoride and full-scale IQ, performance IQ, verbal IQ.
- Reported association with fluoride exposure: Yes: Significant inverse associations between water fluoride and full-scale IQ scores (adjusted β = −10.2 per log-mg/L increase) and between urinary fluoride and full-scale IQ scores (adjusted β = −16.9 per log-mg/g-creatinine increase; CIs not reported, all p-values < 0.001). Arsenic also present, but the effect from arsenic in water or urine was smaller (adjusted β = −6.15 per log-µg/L and −5.72 per l-µg/g-creatinine increase, respectively; CIs not reported, all p-values < 0.01).

#### E.1.7.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information to inform the risk-of-bias evaluation because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: All children in 1st through 3rd grades in three rural areas in Mexico (n = 480) were screened for study eligibility, including age, time at residence, and address. Authors report that the three selected communities were similar in population and general demographic characteristics. Children who had lived in the area since birth and were 6–10 years old were eligible to participate (n = 308). Of the 308 children, 155 were randomly selected and the response rate was 85%, but participation was not reported by area. It was noted, however, that no significant differences in age, sex, or time of residence were observed between participants and non-participants. Time frame for selection was not mentioned but appears to be similar. Sociodemographic characteristics of subjects were provided in Table 1 of the study. There was a significant difference in SES and transferrin saturation, but these were considered in the analysis.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the populations were similar, and differences were noted and addressed in the analysis.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study design or analysis accounted for age, sex, SES, transferrin saturation, weight, height, blood lead levels, and mother's education. Arsenic levels were highly correlated with fluoride levels; however, arsenic and fluoride were evaluated alone, and arsenic was found to have less of an effect on IQ than fluoride. This provides evidence that arsenic had been addressed as a co-exposure and cannot explain the association between fluoride exposure and decreased IQ. Smoking was not addressed and methods for measuring many of the covariates were not reported.
  - [underlined: Potentially important study-specific covariates]: Arsenic
    - Direction/magnitude of effect size: The presence of arsenic in this study, which also demonstrated an association, would likely bias the association away from the null. Although arsenic may contribute to some of the magnitude of the observed effect of fluoride (the exact impact of arsenic on the magnitude cannot be assessed), the presence of arsenic does not fully explain the observed association between fluoride exposure and IQ. The presence of arsenic may affect the magnitude of the association between fluoride and IQ, but it has no impact on the direction of the association.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the methods used to collect the information were valid and reliable and direct evidence that key covariates were addressed.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Of 155 children randomly selected for study participation, 85% responded to enroll. According to the authors, there were no significant differences in age, sex, or time of residence between responders and non-responders. However, no data were provided to support this, and no breakdown of responders/non-responders by region was provided. Data were provided for the 132 children agreeing to participate.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Urine samples were collected on the same day as psychological evaluations and were analyzed for fluoride according to NIOSH Method 8308 (Fluoride in Urine). For QC, a reference standard was also used (NIST SRM 2671a). Urine samples were also analyzed for arsenic by using the Atomic Absorption Spectrophotometer with hydride system and a reference standard for QC. Levels were adjusted for urinary creatinine levels to account for dilution in the spot samples. Tap water samples were collected from each child’s home on the day of biological monitoring. Fluoride was measured with a sensitive, specific ion electrode. Detailed methods are provided including internal quality controls. It was noted that in the high fluoride group, it was common to drink bottled water low in fluoride and to use the tap water only for cooking; therefore, urine was considered the most appropriate measure of exposure. Only children who had lived at the same residence since birth were included.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Neuropsychological profiles were assessed through the WISC-RM (revised for Mexico). This is a well-established test appropriately adjusted for the study population. However, no additional validation was provided (+ for methods). The study report stated that the test assessors were masked to both arsenic and fluoride water levels (++ for blinding). Overall rating for methods and blinding = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: It was reported that an interaction between fluoride and arsenic was measured, but it was noted only in the discussion that the study design precluded testing statistical interaction between fluoride and arsenic. This provides indirect evidence of selective reporting.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that there was selective reporting.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses used were appropriate for the study. Multivariate linear analyses were used to evaluate the associations between fluoride in water and urine and children’s IQ scores. Exposures were natural log-transformed, but the rationale was not provided. Regression diagnostics were not used to test model assumptions for linearity, normality, and homogeneity. The analyses did not account for clustering at the community level. The three selected communities were similar in population and general demographic characteristics. Although the analysis used individual-level exposures rather than area‐level exposures, if the exposure levels within a certain area were highly correlated (which might be expected), then the results might still be biased. However, the overall impact on the effect estimates is expected to be minimal given the use of individual-level data and adjustment for multiple important [underlined: covariates].
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements and blinding of outcome assessors to participants’ fluoride exposure, but it is limited by the cross-sectional study design and the inability to completely rule out the influence of arsenic in the results.

### E.1.8 Saxena et al. (2012)

#### E.1.8.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 12 years
- Study area: Madhya Pradesh, India
- Sample size: 170 children
- Data relevant to the review: Mean IQ grade (not standard scores; higher IQ grades are associated with lower intelligence) by water fluoride quartiles. Correlations between urinary and water fluoride and IQ scores. Adjusted associations between water and urinary fluoride and IQ.
- Reported association with fluoride exposure: Yes: Significant negative correlations between water (r = 0.534) and urinary fluoride and IQ scores (r = 0.542). Significant increase in mean IQ grade (i.e., increase in proportion of children with intellectual impairment) with increasing urinary fluoride.

#### E.1.8.2 Risk of Bias

- Author contacts:
  - Authors were contacted in August 2017 to obtain additional information for risk-of-bias evaluation. Additional information provided by the authors informed the rating decision for the following risk-of-bias domains: Detection (outcome assessment).
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: There was indirect evidence that subjects were similar and were recruited using the same methods during the same time frame. The study participants were selected from a stratified cluster of geographic areas based on fluoride concentration in groundwater. According to the authors, the selected villages were similar in population and demographic characteristics. Data are provided to show the breakdown in SES, parental education, height/age, and weight/height, and no significant differences were noted. Participation was stated to be voluntary, but participation rates were not provided. It is unclear whether the 170 subjects were selected with 100% participation or whether the 170 subjects were all who were asked to participate, but it appears that all subjects participated. Timing of the recruitment was not provided but is assumed to occur during the same time frame.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that subjects were similar and recruited using the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: There was indirect evidence that key covariates, including potential co-exposures, were addressed using reasonable methods. A questionnaire, completed with the assistance of parents, was used to collect information on child characteristics (age, sex, height, weight), residential history, medical history (including illness affecting the nervous system and head trauma), educational level of the head of the family (in years), and SES of the family. The SES was recorded according to the Pareek and Trivedi classification. The nutritional status of the children was calculated using Waterlow’s classification, which defines two groups for malnutrition using height-for-age ratio (chronic condition) and weight for height ratio (acute condition). Within both groups, it categorizes the malnutrition as normal, mildly impaired, moderately impaired, or severely impaired. Urinary lead and arsenic were analyzed using the atomic absorption spectrophotometer. Urinary iodine was measured using the Dunn method. Authors do not report which covariates were included in the multivariate regression models; however, there was no difference in reported demographic characteristics. All subjects were the same age, and there was no difference in iodine, lead, or arsenic between the groups. Mean urinary arsenic levels increased with increasing fluoride even though there was no significant difference by group.
  - [underlined: Potentially important study-specific covariates]: All key [underlined: covariates] were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the methods used to collect the information were valid and reliable and that key [underlined: covariates], including potential co-exposures, were addressed.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Results were provided for all 170 children stated to be included in the study.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence of no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: A sample of 200 mL of drinking water was collected at each child’s home. The fluoride levels were analyzed by a fluoride ion-selective electrode. Each subject was also asked to collect a sample of his/her first morning urine. The fluoride content in the urine was determined using a fluoride ion-selective electrode. QA/QC and LOD were not reported, and urinary dilution was not assessed. Although only current levels were measured, children who had changed their water source since birth were excluded.
    - Direction/magnitude of effect size: Spot urine samples that did not account for dilution could have exposure misclassification. The misclassification is likely non-differential and not likely to bias in any specific direction. Children who had changed water source since birth were excluded, but it was not specifically noted that the fluoride in the water source was stable over the years.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Intelligence was assessed using Raven’s Standard Progressive Matrices and categorized into five grade levels. Although it was not noted that the test was validated to the study population, the test is visual and would be applicable to most populations (+ for methods). There is no mention of blinding by test administrators or evaluators, and the exposure groups come from different geographic areas. It was also not reported who measured the levels of fluoride from the home or urine samples. Correspondence with the study authors indicated that the outcome assessors were blind to the children’s fluoride status (++ for blinding). Overall rating for methods and blinding = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: One-way analysis of variance (ANOVA), simple linear regression, and multiple linear regression were used to compare mean intelligence grades by water fluoride levels and to assess the association between grades and urinary fluoride. Consideration of heterogeneity of variance (for ANOVA) was not reported. Regression diagnostics were not used to test model assumptions for linearity, normality, and homogeneity. Given the ordinal nature of the intelligence grade variable (score from 1 to 5), ordinal logistic regression would have been a more appropriate method. There was no adjustment for area-level clustering in multivariate analyses (although subjects were selected via stratified cluster sampling from two areas). Although the analysis used individual-level exposures rather than area‐level exposures, if the exposure levels within a certain area were highly correlated (which might be expected), then the results might still be biased. However, the overall impact on the effect estimates is expected to be minimal given the use of individual-level data and adjustment for important [underlined: covariates].
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate, and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements and the consideration of key covariates, but it was limited by the cross-sectional study design and lack of addressing dilution in the urine samples.

### E.1.9 Seraj et al. (2012)

#### E.1.9.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 6–11 years
- Study area: five villages, Makoo, Iran
- Sample size: 293 children
- Data relevant to the review: IQ (mean and distribution) assessed by Raven’s Colored Progressive Matrices and presented by fluoride area. Adjusted associations between water fluoride and IQ scores.
- Reported association with fluoride exposure: Yes: Significant inverse association between water fluoride and IQ score (adjusted β = −3.865 per 1-mg/L increase ; CIs not reported); significantly higher IQ score in normal area (97.77 ± 18.91) compared with medium (89.03 ± 12.99) and high (88.58 ± 16.01) fluoride areas.

#### E.1.9.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were selected from five villages in Makoo. The villages were stated to all be rural with similar general demographic and geographic characteristics and were comparable in terms of SES and parental occupations. Children were 6–11 years old. Age, sex, and education were taken into account in the analysis. No other characteristics were provided or discussed. Participation rates were not reported. There is indirect evidence that the populations were similar, and some possible differences were addressed.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that subjects were similar and recruited using the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Age, sex, dental fluorosis intensity, and educational levels (child’s and parents’) were evaluated as important covariates. Other covariates such as smoking were not discussed. Information was obtained from a detailed questionnaire. Lead was measured but found only in low levels in the drinking water throughout the study regions. Iodine in the water was also stated to be measured, and residents were receiving iodine-enriched salt. Arsenic was not addressed, but there is no evidence that arsenic levels would vary across villages in this area. Based on water quality maps, co-exposure to arsenic is likely not a major concern in this area.
  - [underlined: Potentially important study-specific covariates]: Arsenic.
    - Direction/magnitude of effect size: Conceptually, if there were differential amounts of arsenic in the different villages, co-exposure to arsenic could bias the association, with the direction of the bias dependent on where the arsenic was present; however, arsenic was not expected to be a major concern in this study area based on water quality maps.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the methods used to collect the information were valid and that key covariates, including potential co-exposures, were addressed or were not likely to be an issue in the study area.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Attrition was low if it occurred. It was noted that 293 out of 314 children living in the villages were recruited. It is not clear whether 21 children were excluded based on exclusion criteria or whether they refused to participate; however, this accounts for less than 10% of the population, and results were available for all 293 subjects.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exclusion of subjects from analyses was minimal, adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: Exposure was primarily based on area of residence. Fluoride in the groundwater was analyzed by the SPADNS (Sulfophenylazo dihydroxynaphthalene-disulfonate) method, utilizing the 4000 UV-Vis spectrophotometer in the environmental health engineering laboratory of the Public Health School of the Tehran University of Medical Sciences. Specific details were not provided on methods of collection or sample locations or whether these locations represented the primary sources of drinking water for the subjects. Villages were categorized into normal (0.5–1 ppm), moderate (3.1 ± 0.9 ppm), and high (5.2 ± 1.1 ppm) fluoride based on the mean fluoride content of all seasons presumably for the stated 12-year time period. Subjects were stated to be long-life residents of the village. Dental fluorosis was also measured and increased in severity with fluoride levels; however, all areas had some degree of dental fluorosis. Although authors used an average fluoride level in varying seasons over presumably 12 years, they used a less-established method without reporting reliability or validity, and they did not provide data to indicate that the mean was truly representative of the fluoride levels over time and throughout the village. Although dental fluorosis severity increased with increasing fluoride levels, the data could also indicate potential exposure misclassification.
    - Direction/magnitude of effect size: The presence of dental fluorosis in all groups indicates that there may have been different exposures in some children at a younger age. Although there were only about 20 children in the “normal” fluoride group with very mild to mild dental fluorosis, this could bias the results toward the null because those children may have experienced a higher level of fluoride at some point. The other two fluoride groups were exposed to fluoride levels that likely exceeded those in the “normal” fluoride group.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that exposure was assessed using insensitive methods.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Intelligence was evaluated using Raven’s Color Progressive Matrices. This is a well-established method. Although the study authors did not provide data to indicate that the methods were valid in this study population, the test is designed to be culturally diverse (+ for methods). The study report stated that test administrators were blinded to subjects’ exposure status (++ for blinding). Overall rating for methods and blinding = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that outcomes were assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods were reported. However, because the study author did not report the method for obtaining the betas in Table 4 of the study, it is not clear whether these were adjusted or unadjusted regression coefficients.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that all the study’s measured outcomes were reported, but the results were not sufficiently reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical methods for comparisons of IQ level by exposure groups were reasonable (ANOVA, post hoc test, and Kruskal-Wallis test), but consideration of heterogeneity of variance was not reported. Clustering at the village levels was not accounted for in multivariate analyses, which used area‐level water fluoride levels. Because the exposure levels within a certain area are highly correlated (which might be expected), the results are likely to be biased. There was adjustment for some individual-level important covariates, and the children were from five rural areas with similar general demographic and geographic characteristics and were comparable in terms of SES and parental occupations. These factors are expected to mitigate some of the impact of lack of accounting for clustering, and the overall impact on the effect estimates is expected to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding and outcome. Study strengths include addressing potential key covariates, but it was limited by the cross-sectional study design and the group-level exposure data.

### E.1.10 Soto-Barreras et al. (2019)

#### E.1.10.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 9–10 years
- Study area: Chihuahua, Mexico
- Sample size: 161 children
- Data relevant to the review: Water fluoride, urinary fluoride, exposure dose, and dental fluorosis index by IQ grade.
- Reported association with fluoride exposure: No: Results were not presented to evaluate an association between fluoride exposure and IQ but to compare fluoride levels within IQ grades. For this reason, the results of this study are not comparable to other studies that evaluated IQ scores by fluoride exposure levels. We also note that no significant differences in measured fluoride levels across IQ grades were observed.

#### E.1.10.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information to inform the risk-of-bias evaluation because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were selected using a multistage cluster sampling. During the first stage, 13 public elementary schools were randomly selected from a pool of 73 using a cluster sample design. Secondly, only fourth-grade students were included. Authors stated that they wanted to keep the same grade level, but there were no specific details as to why fourth graders were selected as opposed to any other grade. Lastly, only children whose parents or guardians attended and responded to the survey were included. There is no information provided on how the 13 schools selected may have been similar to or different from the 60 schools not selected. There is no information provided on the number of children in the fourth grade to know participant rates. It was only noted that 245 children were examined, but 161 were included after the exclusion rules were applied. Inclusion and exclusion criteria are presented. Reasons for exclusion do not appear to be related to exposure or outcome. Characteristics of participants and non-participants are not compared; however, characteristics of the 161 included children were provided, and any differences were taken into account in the analysis.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposed groups were similar and were recruited using similar methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: No covariates were considered when evaluating associations between fluoride exposure and intelligence; covariates were considered only when evaluating associations between fluoride levels and dental caries. According to Table 4 of the study, there was no significant association between IQ grade and age, sex, parental education, or SES status. No other information was reported or considered. There is no information on potential co-exposures. According to water quality maps, the arsenic prediction indicates a greater than 50% probability of exceeding the WHO guidelines for arsenic of 10 µg/L in areas of Chihuahua, Mexico.
  - [underlined: Potentially important study-specific covariates]: Arsenic.
    - Direction/magnitude of effect size: The impact on the direction and magnitude of effect size is unknown. There is potential for arsenic to occur in the study area, but it is not known how it relates to fluoride exposure. If they occur together in the water, it would likely bias the association away from the null; however, if they occur in different areas, there is potential to bias the association toward the null.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that there is potential for exposure to arsenic that was not sufficiently addressed.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: A total of 161 of 245 children were included in the study. Exclusion criteria are presented and are unrelated to outcome or exposure. For the 161 children, there are no missing outcome data.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+); Probably high risk of bias (−)
  - [underlined: Summary]: Urinary Fluoride (probably low risk of bias): First morning void urine samples were collected based on NIOSH methods. Water samples were also stated to be collected, but it does not appear that methods followed any particular standard, and there is no indication that subjects were provided with collection containers. Analysis was based on a calibration curve using fluoride ion-selective electrode. QC methods were mentioned. Based on results, there were values below detection limits, but LODs or % below LOD were not reported.
    Daily fluoride exposure (probably high risk of bias): Daily fluoride exposure was based on the water fluoride level, drinking water consumption (based on parental report of how many glasses of water consumed), and body weight.
    - Direction/magnitude of effect size: Spot urine samples that did not account for dilution could have exposure misclassification. The misclassification is likely non-differential and is not likely to bias in any specific direction. Daily exposure was based partially on parental report of water consumption. The direction and magnitude of effect is unknown.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure. The daily fluoride exposure is probably high risk of bias because there is indirect evidence that the exposure was assessed using methods of unknown validity.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Intellectual ability was evaluated using Raven’s Colored Progressive Matrices by an independent examiner. Some details were provided, but it was not stated that the tests were assessed blind; however, there is no indication that subjects were from high fluoride areas, and the assessor would not have knowledge of the urine or water fluoride levels. Results for children were converted into a percentile according to age (details not provided), and overall scores were assigned an intellectual grade of I to V as described in the report.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: The Kolmogorov-Smirnov test was used to determine variable distribution. The Kruskal-Wallis test was used to compare exposure levels between IQ grades with Dunn’s post hoc test. Multivariate logistic regression was used to estimate the association between presence of dental caries and various risk factors. Fluoride levels in drinking water and urine and fluoride exposure dose were compared across intellectual grades. Children were from 13 schools selected via stratified cluster sample design. There was no adjustment for clustering at the school level or for the sampling design. Although the analysis used individual-level exposures rather than area‐level exposures, if the exposure levels within a certain school were highly correlated (which might be expected), then the results might still be biased. The large number of clusters (13 schools) makes clustering less of a concern, and the impact on the effect estimates is expected to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in exposure and outcome. Study strengths include individual exposure assessment measurements and blinding of outcome assessor to participants’ fluoride exposure, but it is limited by the cross-sectional study design, lack of accounting for urine dilution, and lack of consideration for potential exposures to arsenic in the study area. Although the study is considered to have low potential for bias overall, the focus of the study was to evaluate the relationship between fluoride exposure and lower rates of dental caries. In terms of evaluating an association between fluoride exposure and IQ scores, the study is limited by the way the data were reported.

### E.1.11 Sudhir et al. (2009)

#### E.1.11.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 13–15 years
- Study area: Nalgonda district (Andhra Pradesh), India
- Sample size: 1,000 children
- Data relevant to the review: Mean IQ grade (not standard scores) or IQ distribution by water fluoride strata (<0.7, 0.7–1.2, 1.3–4.0, and >4.0 ppm).
- Reported association with fluoride exposure: Yes: Significant increase in mean and distributions of IQ grades (i.e., increase in proportion of children with intellectual impairment) with increasing drinking water fluoride levels.

#### E.1.11.2 Risk of Bias

- Author contacts:
  - Authors were contacted in September of 2017 for additional information related to risk-of-bias evaluation, but no response was received.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Children were selected from the same general population during the same time frame and were then broken down into nearly equal exposure groups. A cross-sectional study was conducted among 13–15-year-old school children of Nalgonda district, Andhra Pradesh, between August and October 2006. Data were collected from the school children who were lifelong residents of Nalgonda district, Andhra Pradesh, and who consumed drinking water from the same source during the first 10 years of life. A stratified random sampling technique was used. The entire geographical area of Nalgonda district was divided into four strata based on different levels of naturally occurring fluoride in the drinking water supply. Children were randomly selected from schools in the different strata. It was noted that the 1,000 selected children were equally divided among all four strata; however, each group did not have 250 children (rather, each had 243–267). Participation rates were not reported. Exclusion criteria included children who had a history of brain disease and head injuries, children whose intelligence had been affected by congenital or acquired disease, children who had migrated or were not permanent residents, children with orthodontic brackets, and children with severe extrinsic stains on their teeth. Age and sex data are presented in Table 1 of the study, but this information is not presented by the different fluoride groups.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that subjects were similar and were recruited using the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Data were collected using a self-administered questionnaire and clinical examination. The questionnaire requested information on demographic data (appears to cover age and sex), permanent residential address, staple food consumed, liquids routinely consumed, and aids used for oral hygiene maintenance (fluoridated or non-fluoridated). SES was measured using the Kakkar socioeconomic status scale (KSESS) with eight closed-ended questions related to parental education, family income, father’s occupation, and other factors. All children were asked to fill out the form, and the answers obtained were scored using Kakkar socioeconomic status scoring keys. Based on this scoring, children were divided into three groups: lower class, middle class, or upper class. Age, sex, and SES were not found to be significantly associated with IQ. Other covariates, including smoking, were not addressed. Co-exposures such as arsenic and lead were not addressed; however, there is no indication that lead is a co-exposure in this population, and arsenic is not likely a major concern in this area based on water quality maps.
  - [underlined: Potentially important study-specific covariates]: Key covariates age, sex, and measures of SES were similar between exposure groups; however, arsenic was not considered. Arsenic often occurs in the drinking water along with fluoride in some Indian populations; however, based on water quality maps, this does not appear to be an issue in the Nalgonda district of Andhra Pradesh. Iodine deficiencies are not mentioned.
    - Direction/magnitude of effect size: Conceptually, the presence of arsenic would potentially bias the association away from the null if present with fluoride. Deficiencies in iodine would likely bias the association away from the null if present in areas of high fluoride but toward the null if present in areas of non-high fluoride. Neither of these were considered issues in this study for reasons noted above.
  - Basis for rating: Probably low risk of bias based on indirect evidence that the key covariates were considered, co-exposure to arsenic was likely not an issue in this area, and methods used for collecting the information were valid and reliable.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Results were available for the 1,000 children selected to participate.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence of no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Children were placed into one of four strata based on the level of fluoride in drinking water. Collection of water samples was done in the districts. The placement into strata was based on fluoride levels obtained from documented records of the District Rural Water Works Department. Once the children were assigned to strata, it was confirmed that the fluoride level of their drinking water was within the strata assigned. This was done using the methodology followed in the National Oral Health Survey and Fluoride Mapping 2002–2003. During the initial visits to the schools, the children were interviewed regarding their history of residence and source of drinking water from birth to 10 years. The first child meeting the criteria was given a bottle for water collection, and the next child was given a bottle for collection only if the water source was different from that of a previous child. Children were asked to collect a water sample from the source that was used in the initial 10 years of their life (and that sample was collected the next day). It was not reported whether all bottles were returned. The water samples collected were subjected to water fluoride analysis using an ion-specific electrode, Orion 720A fluoride meter at District Water Works, Nalgonda to confirm the fluoride levels in the water before commencement of clinical examination. LOD and QA/QC details were not reported.
    - Direction/magnitude of effect size: There is some potential for exposure misclassification based on recall of the children on the source of water used in their first 10 years of life. The misclassification is likely non-differential and not likely to bias in any specific direction. Children who had changed water since birth were excluded, but it was not specifically noted that the fluoride in the water source was stable over the years.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably high risk of bias (NR)
  - [underlined: Summary]: Raven’s standard progressive matrices (1992 edition) was used to assess IQ. Raven’s test is a standard test; although there is no information provided to indicate that the methods were reliable and valid in this study population, the test was created to be culturally fair (+ for methods). Blinding or other methods to reduce potential bias were not reported (NR for blinding). No response was received to an email request for clarification in September 2017. Overall rating for methods and blinding = NR.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that the outcome assessors were not blind to participants’ fluoride exposure and could bias the results.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Chi-square test and Spearman rank correlation were used to assess the association between four different fluoride levels and IQ grades. Area-level exposures were used. Clustering of children within the four areas was not accounted for in the analysis; however, because multiple villages were included in each fluoride exposure level, clustering was less of a concern and the impact on the effect estimates was expected to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding and exposure. Study strengths include verification of exposure assessment measurements and consideration of key covariates, but it was limited by the cross-sectional study design and lack of information on blinding during outcome assessment.

### E.1.12 Till et al. (2020)

#### E.1.12.1 Study Details

- Study design: Prospective cohort
- Population: MIREC participants (pregnant mothers and their children aged 3–4 years)
- Study area: 10 cities, Canada
- Sample size: 398 mother-child pairs (247 from non-fluoridated areas, 151 from fluoridated areas; 200 breastfed as infants, 198 formula-fed as infants)
- Data relevant to the review: Adjusted associations between water fluoride concentration (with or without adjusting for maternal urine) in formula-fed or breastfed infants or fluoride intake from formula and IQ scores.
- Reported association with fluoride exposure: Yes: Significant inverse association between water fluoride and IQ by breastfeeding status (adjusted β = −9.26 formula-fed, −6.19 breastfed per 0.5-mg/L increase) and between fluoride intake from formula and performance IQ (adjusted β = −8.76 per 0.5-mg/day increase); significant inverse association between water fluoride and full-scale IQ in formula-fed children (adjusted β = −4.40 per 0.5-mg/L increase); no significant changes in full-scale IQ for water fluoride in breastfed children or fluoride intake from formula-fed children; no significant changes in verbal IQ scores with fluoride exposure.

#### E.1.12.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for the 2020 publication. Authors were contacted in June 2019 for additional information on the Green et al. (2019) publication. Information obtained from that correspondence may have been used for additional information in the 2020 publication.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Pregnant women were recruited between 2008 and 2011 by the MIREC program from 10 cities across Canada. Inclusion and exclusion criteria were provided. Additional details were stated to be available in Arbuckle et al. (2013). A total of 610 children were recruited to participate in the developmental follow-up with 601 children completing all testing. The demographic characteristics of women included in the current analyses (n = 398) were not substantially different from the original MIREC cohort (n = 1,945) or the subset without complete water fluoride and covariate data (n = 203). A table of characteristics of the study population was provided. Approximately half of the children lived in non-fluoridated cities and half lived in fluoridated cities.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposed groups were similar and were recruited with the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Covariates were selected a priori that have been associated with fluoride, breast feeding, and children’s intellectual ability. Final covariates included sex and age at testing, maternal education, maternal race, secondhand smoke in the home, and HOME score. City was considered but excluded from the models. Covariates that were not assessed include parental mental health, iodine deficiency/excess, parental IQ, and co-exposure to arsenic and lead. Co-exposure to arsenic is less likely an issue in this Canadian population because it receives water mainly from municipal water supplies that monitor for lead and arsenic, and the lack of information is not considered to appreciably bias the results. In addition, a previous study on this population (Green et al. 2019) conducted sensitivity analyses on co-exposures to lead and arsenic. Results from these sensitivity analyses support the conclusion that co-exposures to lead and arsenic are not likely a major concern in this study population.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that key covariates were considered and indirect evidence that the methods used to collect the information were valid and reliable and co-exposures were not an issue.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Of 610 children, 601 (98.5%) in the MIREC developmental study who were ages 3–4 years completed the neurodevelopment testing. Of the 601 children who completed the neurodevelopmental testing, 591 (99%) completed the infant feeding questionnaire and 398 (67.3%) reported drinking tap water. It was noted that the demographic characteristics were not substantially different from the original MIREC cohort or the 203 subjects without complete water fluoride or covariate data.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Information on breastfeeding was obtained via questionnaire at 30–48 months. Fluoride concentration in the drinking water was assessed by daily or monthly reports provided by water treatment plants. Water reports were first linked with mothers’ postal codes, and the daily or weekly amounts were averaged over the first 6 months of each child’s life. Additional details can be found in Till et al. (2018). Maternal urinary exposure was used to assess fetal fluoride exposure. Procedures can be found in Green et al. (2019).
    - Direction/magnitude of effect size: There is not any specific direction or magnitude of bias expected. Urinary fluoride levels are reflective of recent exposure. The possibility of exposure misclassification would be similar in all subjects and would be non-differential. For the fluoride intake from formula, exposure was based on the fluoride levels in the water at the residence and the proportion of time that the infant was not exclusively breastfed. This exposure misclassification would also be non-differential.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Intelligence was tested using the Wechsler Preschool and Primary Scale of Intelligence III, which is considered a gold standard test. It is appropriate for both the study population and age group. It was not reported whether the evaluators were blind to the child’s fluoride exposure status during the assessment. Although it is unlikely that the assessors had knowledge of the specific drinking water levels or maternal urine levels, there is potential that the outcome assessors had knowledge of the city the child lived in and whether the city was fluoridated or non-fluoridated. Correspondence with the study authors on the outcome assessment for Green et al. (2019) indicated that it was unlikely that the testers had knowledge of the city’s fluoridation. The same is assumed here. Specific measurements included were identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Regression diagnostics were used to test assumptions for linearity, normality, and homogeneity. There were two potential influential observations (based on Cook’s distance), and sensitivity analyses re-estimated the models without these two variables. Effect modification by breastfeeding status was evaluated. Interestingly, all regression coefficients were divided by 2 to represent change in IQ per 0.5-mg/L change in fluoride. One concern is posed by the lack of accounting for city in the regression models, ideally as a random effect. The authors explored including city as a covariate in the models; however, city was not included either because it was strongly multi-collinear with water fluoride concentration (VIF > 20) (model 1, with water fluoride concentration) or because fluoride intake from formula is a function of water fluoride concentration (assessed at the city level) and was therefore deemed redundant (model 2). However, the models use city-level water fluoride concentrations—and, in sensitivity analyses, adjust for maternal urinary fluoride—which warrants exploration of city as a random effect rather than a fixed effect (as would be the case by having it included as a covariate). Even including individual-level maternal urinary fluoride might not fully account for lack of a city effect, given that the subjects were from six different cities, with half of them fully on fluoridated water. Hence, even individual-level exposures are likely to be correlated at the city level. Based on a previous analysis (Green et al. 2019), it is unlikely that exclusion of city from models (as a fixed or random effect) would significantly impact the effect estimates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements, prospective cohort design, and consideration of key covariates.

### E.1.13 Trivedi et al. (2012)

#### E.1.13.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 12–13 years
- Study area: Kachchh, Gujarat, India
- Sample size: 84 children
- Data relevant to the review: Mean IQ scores and distribution by low and high fluoride villages.
- Reported association with fluoride exposure: Yes: Significantly lower mean IQ score in the high fluoride villages (92.53 ± 3.13) compared with the low-fluoride villages (97.17 ± 2.54) in boys and girls combined (and by sex).

#### E.1.13.2 Risk of Bias

- Author contacts:
  - Authors were contacted in September of 2017 to obtain additional information for risk-of-bias evaluation. Additional information provided by the authors informed the rating decision for the following risk-of-bias domains: Selection, Attrition, Detection (exposure assessment), Detection (outcome assessment).
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: There is insufficient information provided on the sampling methods to determine whether the populations were similar. Although it was noted that samples were obtained for groundwater quality from March to May of 2011, there is no indication that the children were selected at the same time or during a similar time frame. Correspondence with the author indicates that children were selected within a week of the water collection based on random selection of a school in the village. Study participants were selected from six different villages of the Mundra region of Gujarat, India. Subjects were grouped into high and low villages based on the level of fluoride in the drinking water of those villages. The number of subjects per village was not reported, but it was noted that there were 50 children in the low-fluoride group and 34 children in the high fluoride group. It is not clear whether the differences in numbers were based on different participation rates or whether there were fewer children in the high fluoride villages. Recruitment methods, including any exclusion criteria and participation rates, were not provided. SES was stated to be low and equal based on questionnaire information, but the results were not provided. It should also be noted that only regular students (having attendance more than 80%) of standard 6th and 7th grades were selected, but it was not noted whether attendance varied by village. Correspondence with the study author indicated that there was an average of 20 students per class with an average of 40 students per village. It appears that keeping the requirement of 80% attendance was a limiting factor that resulted in different numbers of children by area; however, this was applied similarly to both groups.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that subjects were similar and recruited using the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Children were stated to be students of the 6th and 7th standard grades. Age was not addressed, but the children would all be of similar ages based on the grades included. Results were reported for males and females separately as well as combined. SES and iodine consumption were stated to be analyzed via a questionnaire and were standardized on the basis of the 2011 census of India. Although it was noted in the abstract that the SES was equal (no data provided), the study report did not mention the iodine results. Although arsenic and lead were not considered, the study authors provided physicochemical analyses for the water samples from the six different villages. While the authors did not specifically analyze lead or arsenic in the water samples, these physicochemical analyses suggest that differential lead or arsenic exposure was unlikely. Moreover, based on water quality maps, arsenic was not expected to be a major concern in this study area. According to the information from the water quality maps and the physiochemical analysis of the water provided, there is indirect evidence that neither arsenic nor lead were a concern in this study population.
  - [underlined: Potentially important study-specific covariates]: Key covariates age, sex, and measures of SES were similar between exposure groups; however, arsenic was not considered. Arsenic often occurs in the drinking water along with fluoride in some Indian populations; however, based on water quality maps, arsenic does not appear to be an issue in the study area.
    - Direction/magnitude of effect size: Conceptually, the presence of arsenic would potentially bias the association away from the null if present with fluoride, or toward the null if present in the reference group; however, for reasons noted above, arsenic is not considered a concern in this study population.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the methods used to collect the information were valid and reliable, that potential co-exposures were not an issue, and that key covariates were addressed.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Results were provided for 84 children, but the methods do not indicate how many children were initially selected to participate, nor were any exclusion criteria provided. It was noted in the results that 84 children had their groundwater and urine tested, but it was not noted whether analyses were restricted to these children or whether exposures were assessed in all the children who had IQ measurements. Correspondence with the study author indicated that the main reason for exclusion was a <80% attendance rate, with fluoride and IQ measured on all 84 children who met the criteria.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence of no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Children in villages were grouped based on fluoride levels that were assessed in groundwater (low fluoride villages versus high fluoride villages). The average concentration of these levels was considered to be the levels in the drinking water with confirmation using urinary fluoride levels. The groundwater samples were selected to cover major parts of the taluka and represent overall groundwater quality. Ten samples were obtained from each village. Fluoride was measured in the groundwater using ion exchange chromatography. Although urine levels were also significantly higher in the high fluoride village, no information was provided on how or when the urinary samples were obtained or how they were measured. However, correspondence with the study author indicated that the groundwater and urine fluoride levels were available for all 84 children, indicating that the urine measures were available for the children that had IQ measures. The urine samples were stated to be collected at the same time the second water sample was collected.
    - Direction/magnitude of effect size: Fluoride levels were measured in both the drinking water and urine. Although there is some variability in the measurements, there is no overlap between the two groups, and the urine and drinking water levels in the children support each other. Any potential exposure misclassification would be non-differential, and the impact on the direction and magnitude of the effect size is unknown.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Outcome methods were only noted to be reported in Trivedi et al. (2007), which was scored as follows: IQ was measured in the children of both areas using a questionnaire prepared by Professor JH Shah, copyrighted by Akash Manomapan Kendra, Ahmedabad, India, and standardized on the Gujarati population with a 97% reliability rate in relation to the Stanford-Binet Intelligence Scale (+ for methods). Blinding or other methods to reduce bias were not reported, but correspondence with the study author indicated that the teachers were blind to the status of fluoride. The teachers administered the tests in the presence of a research fellow. It is not completely clear who scored the tests, but it is assumed the teachers (+ for blinding). Overall rating for methods and blinding = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcomes were assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]:
    - Statistical analyses: Mean IQ scores in low and high fluoride villages were compared using a t-test. Consideration of heterogeneity of variances was not reported. Results are reported as means and standard errors of the means, with p-values for significant differences. Area-level exposures were used. There was no accounting for clustering of children within the villages, and comparative analyses did not account for covariates. Urinary fluoride was not considered in the comparative analyses. The lack of individual exposure levels and the lack of accounting for clustering are likely to bias the standard error of the difference in mean IQ levels between the high- and low-fluoride villages and make the differences appear stronger than they actually are.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that the statistical analyses did not account for clustering, and this lack of accounting could bias the association. There were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements and the addressing of potential key covariates, but the study was limited by the cross-sectional study design. Another limitation was the lack of accounting for clustering, which may bias the standard error of the differences, making the effect appear stronger than it actually is; however, this does not change the nearly 5-point difference in IQ scores between the two villages.

### E.1.14 Wang et al. (2012)

#### E.1.14.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 8–13 years [possibly the same study population as Xiang et al. (2003a)]
- Study area: Wamiao and Xinhuai villages located in Sihong County, Jiangsu Province, China
- Sample size: 526 school children
- Data relevant to the review: Mean IQ and % low IQ (<80) by total fluoride intake.
- Reported association with fluoride exposure: Yes: Significantly lower mean IQ in the endemic versus non-endemic regions, as reported in Xiang et al. (2003a); when the high-exposure group was divided into four groups based on fluoride intake, a dose-dependent decrease in IQ and increase in % with low IQ was observed; significant inverse correlation between total fluoride intake and IQ (r = −0.332); significant positive association between total fluoride intake and risk of IQ <80 (adjusted OR = 1.106 per 1-mg/day increase; 95% CI: 1.052, 1.163).

#### E.1.14.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study appears to have the same study population as Xiang et al. (2003a) and Xiang et al. (2011); however, it does not cite these studies as providing additional information, and the numbers of children differ; therefore, it may be a separate analysis on the same villages. The years of testing were not provided, so it cannot be determined whether study subjects were the same. Two villages, Wamiao and Xinhuai, located 64 km apart in Sihong County, Jiangsu Province, were selected for the study. Wamiao is a village in a region with severe endemic fluorosis, and Xinhuai is a village in a non-endemic fluorosis region. Neither village has fluoride pollution from coal or industrial sources. Villages were stated to be similar in terms of annual per capita income, transportation, education, medical conditions, natural environment, and lifestyle. All primary students ages 8–13 years currently in school in either village were surveyed with exclusions noted. Of 243 children from Wamiao, 236 (97.12%) were included, and of 305 children from Xinhuai, 290 (95.08%) were included. No table of subject characteristics was provided.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited using the same methods within the same time frame, with direct evidence that there was no difference in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Logistic regression of low IQ rate and total fluoride intake adjusted for age and sex. Both villages had hand-pumped well water for drinking water, but the authors do not mention whether arsenic was also present in the drinking water. However, a publication by Xiang et al. (2013) in the same study areas indicates that Xinhuai (the low-fluoride area) had significantly higher arsenic levels compared with Wamiao (the endemic fluorosis area), which would bias the association toward the null. Areas were stated to be similar in annual per capita income, transportation, education, medical conditions, natural environment, and lifestyle; however, no details were provided. This study did not address other co-exposures, but other studies on populations in these villages (Xiang et al. 2011; Xiang et al. 2003a) indicate that iodine and lead are not concerns.
  - [underlined: Potentially important study-specific covariates]: Arsenic often occurs in the drinking water along with fluoride in some Chinese populations; however, based on information provided in Xiang et al. (2013), arsenic concentrations were higher in the low-fluoride area compared with the high fluoride area. Because there were significant effects on IQ observed in the high fluoride areas, the impact of co-exposure to arsenic is less of a concern. The presence of arsenic in the control village may cause an underestimation of the effect of fluoride, but despite this potential impact, a significant association between fluoride exposure and IQ was reported.
    - Direction/magnitude of effect size: Presence of arsenic in this study population would potentially bias the association toward the null.
  - [underlined: Basis for rating]: Probably low risk of bias because there is indirect evidence that the key covariates were considered, methods used for collecting the information were valid and reliable, and co-exposures to arsenic and lead and iodine deficiency were not attributing to the association observed in this study. The potential for bias toward the null combined with the reported significant association increases confidence in the observed effect.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Data are reported for all 526 children noted to be included in the study. There is a slight discrepancy in the reported total number of children from the high-fluoride village and the number of participants from the high-fluoride village between this paper (236 participated of 243 total children) and the 2003 and 2011 publications on the same study population (222 of 238). This discrepancy is not explained but is not expected to appreciably bias the results.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+); Probably high risk of bias (−)
  - [underlined: Summary]: Water fluoride (+ probably low risk of bias): Exposure was based on drinking water levels and fluoride intake. Residents in the Wamiao village were divided into five groups based on fluoride levels in the drinking water. Clean, dry polyethylene bottles were used to collect 50 mL of drinking water from each student’s household, and fluoride content was measured.
    Total fluoride intake (− probably high risk of bias): Six families from each of the five Wamiao groups were randomly selected as dietary survey households. Intakes of various foods by each person at each meal and intakes of unboiled water, boiled water, and tea were surveyed for four consecutive days. Methods for food collection were described. Five representative households from each village were selected based on geographic location, population distribution, housing structure, and other conditions. Indoor air samples were collected once daily for five consecutive days; outdoor air was sampled at two points once daily for five days. Methods for determining fluoride content in samples were noted to follow specific guidelines. Calculation of total fluoride intake was stated to follow Appendix A of the People’s Republic of China Health Industry Standard with some details provided. Although it is assumed the method is valid, it was not detailed how each fluoride determination was made for each subject, and it appears that total fluoride intake was determined based on data from select subjects and not all subjects.
    - Direction/magnitude of effect size: There is potential for exposure misclassification based on calculating fluoride intake based on measurements from a few select subjects rather than all subjects. The potential impact on the direction and magnitude of effect size cannot be assessed based on the information provided.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure. The total fluoride intake is probably high risk of bias because there is indirect evidence that the exposure was assessed using methods of unknown validity.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: The IQ of each child was measured with the Combined Raven’s Test for Rural China (CRT-RC) (++ for methods). The test was stated to be administered to the children independently in a school classroom under the supervision of three exam proctors. Testing methods, testing language, and testing conditions were all in strict accordance with the CRT-RC guidebook. Major testing personnel received necessary training by the Psychology Department of East China Normal University. The children undergoing IQ testing and the test scorers were kept double-blind throughout the testing process (++ for blinding). Overall rating = ++.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Logistic regression analysis was used to determine the odds of having low IQ with increasing fluoride intake. Analyses and methods are not well described. There is no mention of what tests were used for the mean IQ comparison by village; however, statistical software (SPSS) was used, suggesting appropriate tests were applied. Simple linear regression analyses were conducted to evaluate associations between total fluoride intake and children’s IQ or low IQ rate. There is no evidence that regression diagnostics were used to test model assumptions for linearity, normality, and homogeneity. Clustering at the village level was not accounted for in the analyses. The overall impact of these factors on effect estimates is expected to be minimal given the use of individual-level data and adjustment for important covariates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements with blinding at outcome assessment but are limited by the cross-sectional study design and lack of individual measurements to calculate fluoride intake. All key covariates were accounted for in the study design or analysis, but there is potential for the presence of arsenic to bias the association toward the null.

### E.1.15 Wang et al. (2020b)

#### E.1.15.1 Study Details

- Study design: Cross-sectional
- Population: School children aged 7–13 years
- Study area: Tianjin City, China [possibly a subset of the children from Yu et al. (2018)]
- Sample size: 571 school children
- Data relevant to the review: Adjusted associations between urine and water fluoride levels and IQ scores.
- Reported association with fluoride exposure: Yes: Significant inverse associations between water fluoride and IQ scores (adjusted β = −1.587 per 1-mg/L increase; 95% CI: −2.607, −0.568) and between urinary fluoride and IQ scores (adjusted β = −1.214 per 1-mg/L increase; 95% CI: −1.987, −0.442) in boys and girls combined. No significant effect modification by sex.

#### E.1.15.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Subjects were from a cross-sectional study conducted in 2015, but no citation was provided on this cohort [presumably the Yu et al. (2018) cohort]. It was noted that the subjects in that cohort were from districts with historically high or normal fluoride levels. Subjects for this study were selected by using a stratified and multistage random sampling approach. Brief description was provided. The study area consisted of three historically high fluoride areas and four non-endemic areas. A flow diagram was provided for inclusion and exclusion, but this detail was given for all children and not by area. Therefore, it cannot be determined whether the participation differed by area. However, there was a 93% recruitment rate, and the 13 excluded due to missing data were not likely excluded due to exposure. Detailed characteristics of the study population are provided. Exclusion criteria included: “children who had congenital or acquired diseases affecting intelligence, or a history of cerebral trauma and neurological disorders, or those with a positive screening test history (like hepatitis B virus infection, Treponema palladium infection and Down's syndrome) and adverse exposures (smoking and drinking) during maternal pregnancy, prior diagnosis of thyroid disease, and children who had had missing values of significant factors (2.2%) were also excluded.”
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposed groups were recruited using similar methods during the same time frame and that any differences between the exposed groups were accounted for in the statistical analyses.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Study authors noted that the study areas were not exposed to other neurotoxins such as lead, arsenic, or mercury nor were they iodine deficient. Final models included age, sex, child’s BMI, maternal and paternal education, household income, and low birth weight. The other covariates that were considered are unclear as the authors only noted that the covariates were selected based on current literature. Reasons for exclusion included history of disease affecting intelligence, history of trauma or neurological disorders, positive screening test history, or exposures such as smoking or drinking during pregnancy. Information was obtained by questionnaire or measurements. Covariates such as parental BMI, behavioral and mental health disorders, IQ, and quantity and quality of the caregiving environment were not considered.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias because there is direct evidence that the key covariates were considered and indirect evidence that the methods for collecting the information were valid and reliable and that co-exposure to arsenic was not an issue in this area.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: A detailed chart of the recruitment process is presented. The study had a 93% recruitment rate, and only 2.2% of subjects with missing data for certain covariates were excluded.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Children provided spot urine samples, presumably at the time of examination. Water samples were randomly collected from public water supplies in each village. Fluoride concentrations were analyzed using fluoride ion-selective electrode according to the national standardized method in China. There is no indication of whether the urine samples accounted for dilution.
    - Direction/magnitude of effect size: Not accounting for dilution could cause some exposure misclassification. The impact on the direction and magnitude of effect size would depend on where the differences occurred.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using acceptable methods that provide individual levels of exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Assessments of IQ scores were conducted by graduate students at the School of Public Health, Tongji Medical College, Huazhong University of Science and Technology. Each team member was assigned a single task, meaning that only one person would have conducted the IQ tests. A Combined Raven’s Test for Rural China was used. Therefore, the test was appropriate for the study population (++ for method). It was noted that the examiner was trained and blind to the exposure (++ for blinding). Overall = ++
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Logistic and multivariate regression models accounting for covariates were used. Results are presented as betas or ORs and 95% CIs. Regression diagnostics were conducted for all models, including examination of multicollinearity, heteroscedasticity, and influential observations. Mediation and interaction analyses were appropriate. There is no evidence that the stratified and multistage random sampling approach for subject selection was accounted for in the analyses by using sampling weights or accounting for clustering using random effect models; however, selected villages were similar in population and general demographic characteristics. Given the use of individual-level data and adjustment for important covariates, the impact on the regression coefficients is likely to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and no other potential threats of risk of bias were identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements but are limited by the cross-sectional study design and lack of accounting for urine dilution. All key covariates were considered in the study design or analysis.

### E.1.16 Xiang et al. (2003a)

#### E.1.16.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 8–13 years
- Study area: Wamiao and Xinhuai villages located in Sihong County, Jiangsu Province, China
- Sample size: 512 school children
- Data relevant to the review: Comparison of IQ (mean and distribution) between Wamiao County (a severe endemic fluorosis area) and Xinhuai County (a non-endemic fluorosis area); additional breakdown of the Wamiao area into five water fluoride exposure groups. Correlations between water fluoride and IQ scores.
- Reported association with fluoride exposure: Yes: Significantly lower IQ scores observed with water fluoride levels of 1.53 mg/L or higher. The percentage of subjects with IQ scores below 80 was significantly increased at water fluoride levels of 2.46 mg/L or higher. Significant inverse correlation between urinary fluoride and IQ (r = −0.164). Mean IQ scores for children in the non-endemic region (100.41 ± 13.21) were significantly higher than the endemic region (92.02 ± 13.00).

#### E.1.16.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Two villages, Wamiao and Xinhuai, located 64 km apart in Sihong County, Jiangsu Province, were selected for this study, which was conducted between September and December 2002. Wamiao is located in a severe fluorosis endemic area, and Xinhuai is located in a non-endemic fluorosis area. Neither village has fluoride pollution from burning coal or other industrial sources. All eligible children in each village were included; children who had been absent from either village for 2 years or longer or who had a history of brain disease or head injury were excluded. In Wamiao, 93% of the children (222 out of 238) were included in the study; in Xinhuai, 95% were included (290 out of 305). The children in Wamiao were divided into five subgroups according to the level of fluoride in their drinking water: <1.0 mg/L (group A), 1.0–1.9 mg/L (group B), 2.0–2.9 mg/L (group C), 3.0–3.9 mg/L (group D), and >3.9 mg/L (group E). Children in Xinhuai (0.18–0.76 mg/L in the drinking water) served as a control group (group F). Demographic characteristics are not presented, and statistical analyses are not adjusted, but mean IQ scores are stratified by age, sex, family income, and parental education.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited using the same methods within the same time frame, with direct evidence that there was no difference in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Although information was stated to be collected on personal characteristics, medical history, education levels of the children and parents, family SES, and lifestyle, only sex, age, family income, and parental education were considered. Potential co-exposures, such as arsenic, were not addressed. A separate publication in 2003 [(Xiang et al. 2003b), letter to the editor] indicated that blood lead levels were not significantly different between the two areas. Although arsenic was not addressed specifically in this publication, Xiang et al. (2013) measured both fluoride and arsenic in the Wamiao and Xinhuai areas. Xinhuai (the low-fluoride area) had significantly higher arsenic levels compared with Wamiao (the endemic fluorosis area). This is likely to bias the association toward the null; however, the study observed a significantly lower IQ score in the endemic fluorosis area. Iodine was tested in a subset of the children and found not to be significantly different between the two groups.
  - [underlined: Potentially important study-specific covariates]: Arsenic often occurs in the drinking water along with fluoride in some Chinese populations; however, based on information provided in Xiang et al. (2013), arsenic concentrations were higher in the low-fluoride area compared with the high fluoride area. Because there were significant effects on IQ observed in the high fluoride areas, the impact of co-exposure to arsenic is less of a concern. The presence of arsenic in the control village may cause an underestimation of the effect of fluoride, but despite this potential impact, there was still a significant association between fluoride exposure and IQ.
    - Direction/magnitude of effect size: Presence of arsenic in this study population would potentially bias the association toward the null.
  - [underlined: Basis for rating]: Probably low risk of bias because there is indirect evidence that the key covariates were taken into account, methods used for collecting the information were valid and reliable, and co-exposures to arsenic and lead and iodine deficiency were not attributing to the effect observed in this area. The potential for bias toward the null, combined with the reported significant association increases confidence in the observed effect.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Data are complete. IQ results were reported for all 512 children included in the study (222 in the endemic area and 290 in the nonendemic area).
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that there was no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Exposure was based on drinking water and urinary levels of fluoride. The two study areas were selected to reflect a severe endemic area and a non-endemic area. Drinking water was collected from wells, and early-morning spot urine samples were collected from a randomly selected subsample of children. Both water and urine samples were measured using fluoride ion-selective electrode, but no quality control was discussed. Both absolute and creatinine-adjusted urine results were reported.
    - Direction/magnitude of effect size: There is potential for exposure misclassification because only current levels were assessed. Migration of subjects in or out of the area was not assessed, but the study authors noted that if the children had been absent from the village for 2 or more years, they were excluded. Misclassification would likely be non-differential, which could likely bias the association in either direction.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: The IQ of each child was measured with the Combined Raven’s Test for Rural China (CRT-RC) (++ for methods). The test was stated to be administered to the children independently in a school classroom, in a double-blind manner, under the supervision of an examiner and two assistants, and in accordance with the directions of the CRT-RC manual regarding test administration conditions, instructions to be given, and test environment (++ for blinding). Overall rating = ++
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: There is no mention of the tests conducted, but data were stated to be analyzed using SAS, suggesting appropriate tests were applied. Results provided in the tables indicate that t-tests comparing IQ values between the villages (overall and by sex) were conducted, but it was not reported that heterogeneity of variance was assessed. In addition, correlations between IQ and age, family income, and parents’ education level were tested with Pearson’s correlation. There is no evidence that a test for trend was conducted to evaluate the stated “significant inverse concentration-response relationship between the fluoride level in drinking water and the IQ of children.”
    - A potential concern raised by the NASEM (2020) committee’s review was the lack of accounting for relationships in exposure between persons from the same village. Given only two villages were included and the analyses consisted of village-level comparisons (no use of individual-level covariate data), it is likely that the standard error of the difference in mean IQ between fluoride in water exposure groups will be biased, making differences appear stronger than they actually are. Without controlling for village effects and given the large differences in fluoride concentrations and IQ levels between villages, the apparent dose-response relationship could be due to a village effect in addition to a fluoride effect. However, a dose-response relationship is apparent within the “exposed” village, diminishing the concern for a village-only effect and likely minimizing the impact on the effect estimates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that statistical analyses were appropriate and that there were no other threats of risk of bias.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements and blinding of outcome assessor to exposure but is limited by the cross-sectional study design and lack of accounting for urine dilution. All key covariates were considered in the study design or analysis, but there is potential for the presence of arsenic to bias the association toward the null.

### E.1.17 Xiang et al. (2011)

#### E.1.17.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 8–13 years [same study population as Xiang et al. (2003a)]
- Study area: Wamiao and Xinhuai villages located in Sihong County, Jiangsu Province, China
- Sample size: 512 school children
- Data relevant to the review: Mean IQ scores and odds ratio for having an IQ <80 by serum fluoride quartiles.
- Reported association with fluoride exposure: Yes: Significant linear trend across quartiles of serum fluoride and children’s IQ score <80 (adjusted ORs for Q1 and Q2; Q1 and Q3; and Q1 and Q4, respectively: 1; 2.22 [95% CI: 1.42, 3.47]; and 2.48 [95% CI: 1.85, 3.32]); significant associations observed at levels ≥0.05 mg/L serum fluoride.

#### E.1.17.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study population was the same as that used in the Xiang et al. (2003a) study, but a few more measurements were available and different analyses were conducted. The comparison population was considered the same based on the study populations being recruited from similar populations, using similar methods, during the same time frame. Demographic characteristics were not provided.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited using the same methods within the same time frame, with direct evidence that there was no difference in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: As was noted in the 2003 publication (Xiang et al. 2003a), information was collected on personal characteristics, medical history, education levels in the children and parents, family SES, and lifestyle. In the logistic regression model age and sex were adjusted for in the analysis. In the previous report, no significant associations were observed between groups for family income and parents’ education (Xiang et al. 2003a). Urinary iodine and blood lead levels were also stated to be measured and were noted not to be significantly different between the groups. Although the iodine levels were reported in the previous publication, the lead levels were not and neither were the methods. Lead information is reported in a letter to the editor (Xiang et al. 2003b) and was not significantly different between the areas. Although arsenic was not addressed specifically in this publication, Xiang et al. (2013) measured both fluoride and arsenic in the Wamiao and Xinhuai areas. Xinhuai (the low-fluoride area) had significantly higher arsenic levels compared with Wamiao (the endemic fluorosis area). This is likely to bias the association toward the null; however, the study observed a significantly lower IQ score in the endemic fluorosis area and with increasing serum fluoride.
  - [underlined: Potentially important study-specific covariates]: Arsenic often occurs in the drinking water along with fluoride in some Chinese populations; however, based on information provided in Xiang et al. (2013), arsenic concentrations were higher in the low-fluoride area compared to the high fluoride area. Because there were significant effects on IQ observed in the high fluoride areas, the impact of co-exposure to arsenic is less of a concern. The presence of arsenic in the control village may cause an underestimation of the effect of fluoride, but despite this potential impact, there was still a significant association between fluoride exposure and IQ.
    - Direction/magnitude of effect size: Presence of arsenic in this study population would potentially bias the association toward the null.
  - [underlined: Basis for rating]: Probably low of risk bias because there is indirect evidence that the key covariates were considered, methods used for collecting the information were valid and reliable, and co-exposures to arsenic and lead and iodine deficiency were not attributing to the effects observed in this area. The potential bias toward the null, combined with the reported significant association increases confidence in the observed effect.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Data are reported for all 512 children noted to be included in the study.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that there was no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Fluoride levels were measured in serum with a fluoride ion-selective electrode. A fasting venous blood sample was used. No details are provided on validation (including correlation with drinking water levels) or QA. Children who did not reside in their village for at least 2 years were excluded. Results were provided in quartiles, but the authors combined the lower two quartiles. After combining the two lower quartiles, the exposure levels ranged from <0.05 mg/L (Q1 + Q2) to >0.08 mg/L (Q4).
    - Direction/magnitude of effect size: Serum fluoride may not be the best estimate for exposure. There is potential for exposure misclassification because only current levels were assessed. Migration of subjects in or out of the area was not assessed, but the study authors noted that if the children had been absent from the village for 2 or more years, they were excluded. Misclassification would likely be non-differential, which could bias results in either direction.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: IQ was assessed as part of the 2003 evaluation. IQ was measured with the Combined Raven’s Test for Rural China, which is appropriate for this population (++ for methods). Although this study does not provide details, the original study article from 2003 provides specific details. The study authors indicate in the 2003 publication that the tests were conducted in a double-blind manner, and these are the same results and population (++ for methods). Overall rating = ++
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses conducted were appropriate for the study. Chi-square tests were used to compare categorical variables, and multiple logistic regression was used to evaluate the association between serum fluoride levels and risk of low IQ. A potential concern raised by the NASEM (2020) peer review was the lack of accounting for relationships in exposure between persons from the same village. Although only two villages were included, in the analyses that consisted of village-level comparisons, it is likely that the standard error of the difference in mean IQ between villages is biased. This is less of a concern for the mean IQ comparisons across quartiles of serum fluoride levels and for the logistic regression analyses of risk of low IQ and individual-level serum fluoride levels. Without controlling for village effects and given the large differences in fluoride concentrations and IQ between villages, the apparent dose-response relationship could be due to a village effect in addition to a fluoride effect. However, the dose-response relationship is still present within the “exposed” village, diminishing the concern for a village-only effect and likely minimizing the impact on the effect estimates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements with blinding at outcome assessment but is limited by the cross-sectional study design and use of serum concentrations. All key covariates were considered in the study design or analysis, but there is potential for the presence of arsenic to bias the association toward the null.

### E.1.18 Yu et al. (2018)

#### E.1.18.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 7–13 years
- Study area: Tianjin City, China
- Sample size: 2,886 school children
- Data relevant to the review: IQ for normal (≤1 mg/L) versus high (>1 mg/L) water fluoride; adjusted associations between water and urine fluoride and IQ scores.
- Reported association with fluoride exposure: Yes: Significant difference in mean IQ scores in high water fluoride areas (>1.0 mg/L; 106.4 ± 12.3 IQ) compared to the normal water fluoride areas (≤1.0 mg/L; 107.4 ± 13.0). Distribution of IQ scores was also significantly different (p = 0.003). Significant inverse association between water fluoride and IQ scores (adjusted β = −4.29 per 0.5-mg/L increase; 95% CI: −8.09, −0.48).

#### E.1.18.2 Risk of Bias

- Author contacts:
  - Authors were contacted in September 2018 to obtain additional information for the risk-of-bias evaluation. Additional information provided by the authors informed the rating decision for the following risk-of-bias domains: Detection (outcome assessment).
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: School children (2,886), aged 7–13 years, were recruited from the rural areas of Tianjin City, China. After exclusion, 1,636 children were assigned to the “normal-fluoride” exposure group, and 1,250 were assigned to the “high-fluoride” exposure group based on a cut-off water fluoride level of 1.0 mg/L. A multistage random sampling technique, stratified by area, was performed to select representative samples among local children who were permanent residents since birth. Detailed characteristics of the study population were provided. Exclusion criteria included: 1) children who had congenital or acquired diseases affecting intelligence, 2) children with a history of cerebral trauma and neurological disorders, 3) children with a positive screening test history (like hepatitis B virus infection, Treponema palladium infection and Down's syndrome), and 4) children with adverse exposures (smoking and drinking) during maternal pregnancy. A table of characteristics was provided by fluoride level with differences adjusted in the analysis.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposed groups were recruited using similar methods during the same time frame and that any differences between the exposed groups were considered in the statistical analyses.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Demographic data were collected by trained investigators during a face-to-face interview with the recruited children and their parents. Questionnaires were not stated to be validated. The developmental status of the children was further assessed by calculation of BMI, and all measurements were conducted by nurses based on recommended standard methods. Variables that presented differential distribution between the normal-fluoride and high-fluoride exposure groups were adjusted in the linear regression analysis of IQ data and included age, sex, paternal and maternal education levels, and low birth weight. Children exposed to smoking in utero were excluded from the study. Sensitivity analyses were conducted by modifying covariates adjusted in multivariable models among demographics (age and sex); development (BMI); socioeconomics (maternal education, paternal education, and household income); history of maternal disease during pregnancy (gestational diabetes, malnutrition, and anemia); and delivery conditions (hypoxia, dystocia, premature birth, post-term birth, and low birth weight). None of the study sites selected were in areas endemic for iodine deficiency disorders, nor were other potential neurotoxins like lead, arsenic, and mercury present. Variables such as parental BMI and behavioral and mental health disorders were not addressed.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that methods of obtaining the information were valid and reliable and direct evidence that all key covariates and co-exposures were considered.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: There were 1,636 children assigned to the “normal-fluoride” exposure group based on water fluoride and 1,250 children assigned to the “high-fluoride” exposure group. Exclusion from the original group of 2,886 children was adequately described. A total of 2,380 children provided urine samples. There is no indication that the data presented excludes any additional children or urine samples, but results do not indicate a sample size for all results.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: According to the annual surveillance data from the CDC, the drinking water sources and water fluoride concentrations in each village had remained at stable levels over the past decade. During the investigation, water samples were collected randomly from the public water supplies in each village. Spot (early-morning) urine samples from every child and water samples from each village were collected in pre-cleaned, labeled polythene tubes and transported to the lab within 24 hours while frozen. Samples were stored at −80°C until analysis. Concentrations of fluoride ions (mg/L) were analyzed using the national standardized ion-selective electrode method in China; the detection limit was 0.01 mg/L. Samples were diluted with an equal volume of total ionic strength adjusted buffer (TISAB) of pH 5–5.5 for optimal analysis. Double-distilled deionized water was used throughout the experiment. There is no reporting of any QC methods.
    - Direction/magnitude of effect size: Spot urine samples may lead to non-differential exposure misclassification. The large population size likely dilutes any potential effects of occasional misclassification. Because the drinking water sources of fluoride had been noted to be stable for the past decade and the children were 13 years or younger, there would only be exposure misclassification if there was a lot of migration between areas.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: IQ scores were measured using the second edition of the Combined Raven’s Test–The Rural in China (CRT-RC2) for children aged 7–13 years (++ for methods). The test was completed by each participant within 40 minutes, according to the instruction manual. For each test, 40 children were randomly allocated to one classroom to take the test independently under the supervision of four trained professionals. There is no mention of whether the evaluators were blinded to the fluoride group of each child (normal vs. high fluoride) or whether there were steps taken to ensure consistency in scoring across the evaluators. It is also not clear whether the 40 children randomly assigned to the classroom were specific to the village or whether a local center was used. Correspondence with the study authors indicated that the four professionals worked together throughout the examination without knowledge of the child’s fluoride exposure (++ for blinding).
  - [underlined: Basis for rating]: Definitely low risk of bias based on the direct evidence that the outcome was assessed using instruments that were valid and reliable, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses used were appropriate for the study. Univariate and multivariable piecewise linear regression models were used to estimate the associations between water fluoride or urinary fluoride levels and IQ scores. Multiple logistic regression analysis was used to evaluate the association between water or urinary fluoride levels and IQ degree using the normal intelligence group as the control. Sensitivity analyses were conducted. There is no evidence that residual diagnostics were used to examine model assumptions or that the complex sampling design (stratified multistage random sampling) was accounted for in the analysis using sampling weights and adjustment for clustering. The impact of these factors on the effect estimates is expected to be minimal given the use of individual-level data and adjustment for numerous important covariates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements with blinding at outcome assessment but is limited by the cross-sectional study design and lack of accounting for urine dilution. All key covariates, including potential co-exposures, were considered in the study design or analysis.

### E.1.19 Zhang et al. (2015b)

#### E.1.19.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 10–12 years
- Study area: Tianjin City, China
- Sample size: 180 children
- Data relevant to the review: Mean IQ scores by control and high fluoride groups; correlations between water, serum, or urinary fluoride and IQ scores; adjusted associations between urinary fluoride levels and IQ scores (by genotypes).
- Reported association with fluoride exposure: Yes: Significant inverse correlation between children’s serum fluoride (r = −0.47) and urinary fluoride (r = −0.45) and IQ scores; significant difference in mean IQ score for high-fluoride area (defined as >1 mg/L in drinking water; 102.33 ± 13.46) compared with control area (<1 mg/L; 109.42 ± 13.30).

#### E.1.19.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Subjects were similar and recruited during the same time frame using the same methods. Authors recruited schoolchildren from a high fluoride area (1.40 mg/L) and a control area (0.63 mg/L) in Tianjin City, China. In accordance with the principles of matching social and natural factors such as educational standard, economic situation, and geological environments as much as possible, two areas with different fluoride concentrations in the groundwater were selected by a stratified cluster random sampling of this region. A total of 180 5th grade children aged 10 to 12 years from two primary schools located 18 km apart in the Jinnan District were recruited—Gegu Second Primary School (from an endemic fluorosis area) and Shuanggang Experimental Primary School (from a non-endemic fluorosis area). The areas are not affected by other drinking water contaminants, such as arsenic or iodine. All subjects were unrelated ethnic Han Chinese and residents in Tianjin with similar physical and mental health status. The authors excluded subjects with known neurological conditions, including pervasive developmental disorders and epilepsy. Descriptive statistics of the study population are presented by exposure group in Table 1 of the study. A number of potential differences were considered in the statistical analyses.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposure groups were similar and recruited using similar methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Covariates included in the statistical models were age, sex, educational levels of parents, drinking water fluoride (mg/L), and levels of thyroid hormones (T3, T4, and TSH). Authors report that the study areas were not affected by other contaminants such as arsenic or iodine, and residents were of similar physical and mental health status. Other important covariates (maternal demographics, smoking, reproductive health) were not considered. Covariate data were obtained from a study questionnaire.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the methods used to collect the information were valid and reliable and direct evidence that key covariates, including potential co-exposures, were considered.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Results are complete for the 180 children selected for the study.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that there was no attrition.
- Exposure:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Drinking water samples (10 mL) were collected from the tube wells of each child’s household. Three fasting venous blood samples were also collected. Urine samples were collected in the early morning before breakfast. Fluoride content in drinking water (W-F), serum (S-F), and urine (U-F) was measured using an ion analyzer EA940 with a fluoride ion-selective electrode (Shanghai Constant Magnetic Electronic Technology Co, Ltd, China), according to the China standard GB 7484-87. All reference solutions for the fluoride determinations were double-deionized water. Parallel samples were set for determination, and averages were taken. The quantitation limits of this method for W-F, S-F, and U-F were 0.2, 0.012, and 0.5 mg/L, respectively. Recovery rates for this method were in the range of 94.3%–106.4%. The intra- and inter-assay coefficients of variation for fluoride were 2.7% and 6.7%, respectively. Dilution of the urinary fluoride was not addressed.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: A Combined Raven’s Test for Rural China (CRT-RC) was taken to evaluate the IQ of each child (++ for methods). The study report stated that all tests were administered at school by a trained examiner who was masked to participants’ drinking water fluoride levels (++ for blinding). Overall rating for methods and blinding = ++.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All results outlined in the abstract, introduction, and methods sections were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Associations between serum and urinary fluoride levels and IQ score were estimated using general linear models and multivariate linear regression by COMT variant. Normality (Kolmogorov-Smirnov test) was evaluated for all continuous variables. There is no evidence that residual diagnostics were used to examine model assumptions or that the complex sampling design (stratified multistage random sampling) was accounted for in the analysis using sampling weights and adjustment for clustering. The impact of these factors on the regression effect estimates is expected to be minimal given the use of individual-level data and adjustment for numerous covariates.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements, blinding of outcome assessor to participants’ fluoride exposure, and consideration of key covariates including potential co-exposures.

## E.2 Other Neurodevelopmental Studies

### E.2.1 Barberio et al. (2017b)

#### E.2.1.1 Study Details

- Study design: Cross-sectional
- Population: Canadian Health Measures Survey (cycles 2 and 3) participants (children aged 3–12 years)
- Study area: general population of Canada
- Sample size: 2,221 children (1,120 from Cycle 2, 1,101 from Cycle 3)
- Data relevant to the review: Adjusted associations between urinary fluoride and learning disability or ADHD (Cycle 2 only) assessed by parent or child self-report.
- Reported association with fluoride exposure: Yes: Significant positive association between urinary fluoride (unadjusted for creatinine) and risk of learning disability (adjusted OR = 1.02 per 1-µmol/L increase; 95% CI: 1.00, 1.03) when Cycles 2 and 3 were combined. No significant associations with creatinine-adjusted or specific gravity-adjusted urinary fluoride. No significant association between urinary fluoride and ADHD.

#### E.2.1.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: The comparison groups were selected from Cycles 2 and 3 of the Canadian Health Measures Survey. This is a nationally representative sample of residents living in 10 provinces, with clear exclusion criteria provided. Exclusion represented only about 4% of the target population (all Canadian residents 3–79 years old living in 10 provinces). A table of characteristics of the study population is provided.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the subjects were recruited from the same population using the same methods during the same time frame, and exposure groups were similar.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study adjusted for sex, age (3–12 years old), household education, and household income adequacy. Variables to discern fluoride source, including drinking water and dental products, were also considered. Cycle 2 data also included adjustments for: 1) children for whom tap water (vs. bottled or other) was the primary source of drinking water at home or away from home and 2) children who had lived in their current home for 3 or more years. Covariates such as parental behavioral and mental health disorders, smoking, and nutrition were not discussed. The study used data from the Canadian Health Measures Survey, which consists of a nationally representative sample of Canadians. Most Canadians (~89%) receive water from municipal water supplies, which monitor for levels of lead and arsenic. Therefore, co-exposure to lead and arsenic are less likely an issue in this population and the lack of information is not considered to appreciably bias the results.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that key covariates were addressed and indirect evidence that the methods used to collect the information were valid and reliable and that co-exposures were not an issue.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Covariate data were missing for less than 5% of all analyses, apart from household income; household income was reported for only 71%–77% of participants and was imputed for the remainder.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Estimates of urinary fluoride (µmol/L) from spot urine were available for a subsample of respondents. Analysis was performed under standardized operating procedures at the Human Toxicology Laboratory of the Institut National de Santé Publique du Québec (accredited under ISO 17025). Fluoride content of urine samples was analyzed using an Orion pH meter with a fluoride ion-selective electrode with limits of detection of 20 μg/L (Cycle 2) and 10 μg/L (Cycle 3). Urinary dilution was addressed by using creatinine-adjusted levels as well as specific gravity-adjusted levels. In Cycle 3 only, estimates of the fluoride concentration of tap water samples collected from randomly selected households were available. The subsample of households selected for tap water sample collection corresponded to the person-level urine fluoride subsample. Analysis of the fluoride concentration of tap water was performed using a basic anion exchange chromatography procedure, with a limit of detection of 0.006 mg/L. QC methods were not addressed.
    - Direction/magnitude of effect size: There is not any specific impact on the direction or magnitude of effect size expected. Urinary fluoride levels are reflective of a recent exposure. Having a single concurrent measurement may not be reflective of the exposure associated with the outcome, but if subjects lived in the same area throughout life, the exposure may be an adequate representation. Although there is possible exposure misclassification, it would likely be non-differential.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: The primary outcome variable, diagnosis of a learning disability by a health professional, was based on a single item from a household survey asked to all respondents: “Do you have a learning disability?” Answer options were: “yes,” “no,” “don’t know,” or the participant refused to answer. For Cycle 2, those who indicated having a learning disability were also asked what kind, with the answer options of: “ADD,” “ADHD,” “dyslexia,” or “other.” This question was omitted in Cycle 3, and the reason for omission was not described. Parents or guardians answered all questions for children aged 3–11 years, while children 12 years and older answered questions themselves. The self-reporting of a learning disability did not appear to have been confirmed by medical records or a health professional (− for methods based on self-report of diagnosis by a health care professional; also, in Cycle 3, no specific disabilities were described). Blinding was not a concern as spot urine samples were sent to a separate lab, and self-reports would not have knowledge of their urine or tap water exposure level (+ for blinding). Overall rating = −.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that the outcome was measured using an insensitive method in the study population.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods sections were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]:
    - Statistical analyses: Logistic regression analyses, adjusted and unadjusted for covariates, examined the associations between fluoride exposure and diagnosis of learning disability. Analyses were performed for Cycle 2 only (urinary fluoride and type of learning disability diagnosis), Cycle 3 only (urinary fluoride, water fluoride, and learning disability diagnosis), and Cycles 2 and 3 combined. Analyses used survey weights and bootstrapped weights to ensure proper computation of variance estimates. Results are reported as unadjusted and adjusted ORs with 95% CIs.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding and exposure. Study strengths include individual exposure assessment measurements and the consideration of key covariates but were limited by the cross-sectional study design and insensitive outcome measures.

### E.2.2 Bashash et al. (2017)

#### E.2.2.1 Study Details

- Study design: Prospective cohort
- Population: Early Life Exposures in Mexico to Environmental Toxicants (ELEMENT) participants (pregnant mothers and their children aged 4 or 6–12 years).
- Study area: Mexico City, Mexico
- Sample size: 299 mother-child pairs, of whom 287 had data for the general cognitive index (GCI).
- Data relevant to the review: Adjusted and unadjusted associations between maternal or child’s urinary fluoride concentrations and GCI.
- Reported association with fluoride exposure: Yes: Significant inverse association between maternal urinary fluoride and GCI score (adjusted β = −3.15 per 0.5-mg/L increase; 95% CI: −5.42, −0.87). No significant associations with children’s urinary fluoride.

#### E.2.2.2 Risk of Bias

- Author contacts:
  - Authors were contacted for additional information on whether clustering was addressed. The authors provided results from additional models with cohort as a random effect, which informed the rating decision for the following risk-of-bias domains: Other.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Study participants were selected from two different cohorts from three hospitals in Mexico City that serve low-to-moderate income populations. One cohort was from an observational study of prenatal lead exposure and neurodevelopmental outcomes, and the other was from a randomized trial of the effect of calcium on maternal blood lead levels. The authors state that participants had no history of psychiatric disorders, high-risk pregnancies, gestational diabetes, illegal drug use, or continuous prescription drugs, but information on smoking habits was not included. Study populations appear to be similar, but there may be some differences because subjects were selected from two different cohorts that were recruited during slightly different time periods.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar despite the subjects coming from different original study populations for whom different methods were used for recruitment.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Data were collected via questionnaire on maternal age, education, marital status at first prenatal visit, birth order, birth weight, gestational age at delivery, maternal smoking, maternal IQ, and HOME scores. All models were adjusted for gestational age at birth, sex, birth weight, birth order, age at testing, maternal marital status, smoking history, maternal age at delivery, maternal IQ, education, and cohort, with additional testing for children’s urinary fluoride, mercury, lead, and calcium. Sensitivity analyses were additionally adjusted for HOME score. Covariates not considered included BMI, iodine deficiency, arsenic, and maternal mental health and nutrition. Arsenic is assumed not to be a potential co-exposure in this population as the study authors did not discuss it as an issue, although other co-exposures were considered. Arsenic is included in the water quality control program in Mexico City and thus is not considered a concern in this population.
  - [underlined: Potentially important study-specific covariates]: All key covariates were addressed.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that key covariates, including other potential co-exposures, were considered, and indirect evidence that the methods used to collect the information were valid and reliable and that arsenic was not likely to be an issue in this study population.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Although there was a large amount of attrition, the study authors clearly describe all reasons for attrition and also provide characteristics to compare those participants included to those excluded. There were some slight differences between those included and those excluded, but there is no evidence to indicate that the attrition would potentially bias the results.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Urinary fluoride concentrations were determined in spot urine samples (second morning void) collected from mothers (during at least one trimester) and children ages 6–12 years. Fluoride content was measured using ion-selective electrode-based assays. Quality control methods were described, including between-laboratory correlations. All samples were measured in duplicate. Extreme outliers were excluded. Urinary dilution was addressed by using creatinine-adjusted levels.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Outcome was assessed using the McCarthy Scales of Children’s Abilities (MSCA) in 4-year-old children (translated into Spanish) and the Wechsler Abbreviated Scale of Intelligence (WASI) in 6–12-year-olds. The WASI is a well-established test, and the validity of both tests is well documented by the authors. Inter-examiner reliability was evaluated and reported with a correlation of 0.99 (++ for methods). The study report stated that psychologists were blind to the children’s fluoride exposure (++ for blinding). Overall rating for methods and blinding = ++.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses used were appropriate for the study. Statistical tests of bivariate associations (using Chi-square tests for categorical variables and analysis of variance [ANOVA]) were used to compare the means of the outcomes or exposures within groups based on the distribution of each covariate. Generalized additive models (GAMs) were used to estimate the adjusted association between fluoride exposure and measures of children’s intelligence. Residual diagnostics were used to examine model assumptions and identify any potentially influential observations. Results are reported as adjusted regression slopes and 95% CIs. In sensitivity analyses, regression models accounted for clustering at the cohort level by using cohort as a fixed effect in the models. Although using cohort as a random effect would be more appropriate, using individual-level exposure data and accounting for numerous important covariates in the models likely captured the cohort effect. Additional models with cohort as a random effect were also subsequently made available via personal communication with the study authors and showed similar results to the main model.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements, blinding of outcome assessor to participants’ fluoride exposure, and the prospective cohort study design.

### E.2.3 Bashash et al. (2018)

#### E.2.3.1 Study Details

- Study design: Prospective cohort
- Population: ELEMENT participants (pregnant mothers and their children aged 6–12 years)
- Study area: Mexico City, Mexico
- Sample size: 210 mother-child pairs
- Data relevant to the review: Adjusted associations between maternal urinary fluoride concentrations and ADHD and other attention/impulsivity scores.
- Reported association with fluoride exposure: Yes: Significant positive associations between maternal urinary fluoride and Conners’ Rating Scales-Revised (CRS-R) scores, including Cognitive Problems and Inattention Index (adjusted β = 2.54 per 0.5-mg/L increase; 95% CI: 0.44, 4.63), DSM-IV Inattention Index (adjusted β = 2.84 per 0.5-mg/L increase; 95% CI: 0.84, 4.84), DSM-IV ADHD Total Index (adjusted β = 2.38 per 0.5-mg/L increase; 95% CI: 0.42, 4.34), and ADHD Index (adjusted β = 2.47 per 0.5-mg/L increase; 95% CI: 0.43, 4.50).

#### E.2.3.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Participants were a subset of mother-child dyads enrolled in various longitudinal birth cohort studies of the Early Life Exposure in Mexico to Environmental Toxicants (ELEMENT) project. Subjects were included from two of the four cohorts for which maternal urinary samples were available. Participants in cohort 2A were recruited between 1997 and 1999, and participants in cohort 3 were recruited from 2001 to 2003. Inclusion and exclusion criteria were applied consistently across the two cohorts. A table of subject characteristics was provided in the study, and any differences were considered in the analysis. Study populations appear to be similar, but there may be some differences because subjects were selected from two different cohorts: one from an observational study on prenatal lead exposure and the other from a randomized trial on the effects of calcium on blood lead levels. In addition, they were recruited from slightly different time periods.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposed groups were similar, and any differences were considered in the analysis.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Questionnaires were used to collect information on maternal age, maternal education, history of smoking, and marital status during the first pregnancy visit. Child information at birth included birth weight, sex, birth order, and gestational age as calculated by the nurse. Mothers also responded to an SES questionnaire during the visit when the psychometric tests were administered. The Home Observation for Measurement of the Environment (HOME) score was evaluated in a subset of participants. Covariates were selected a priori. Models were adjusted for maternal age at delivery, years of education, marital status, smoking history, gestational age at birth, age at outcome assessment, sex, birth order, SES, cohort, and calcium intervention. Arsenic is included in the water quality control program in Mexico City and is not considered a concern in this population.
  - [underlined: Potentially important study-specific covariates]: None identified, although this study did not specifically address arsenic or other co-exposures. Bashash et al. (2017) addressed potential co-exposure to lead and mercury but did not address arsenic. Arsenic was potentially addressed as part of the water quality program in Mexico City.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias based on direct evidence that key covariates were addressed, and indirect evidence that the methods used to collect the information were valid and reliable and that arsenic and other potential co-exposures were not likely to be an issue in this study population.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Although there was a large amount of attrition from the original cohorts, it was unlikely related to outcome or exposure, and there were very little missing data from those included in the study. Of the 231 mothers with a minimum of one maternal urine fluoride measurement and matching outcome identified for the project, only 17 were excluded based on incomplete demographic and outcome information.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Mothers provided at least one spot urine sample during pregnancy. As described in Bashash et al. (2017), urinary concentrations were determined on second morning void. Fluoride content was measured using ion-selective electrode-based assay. Bashash et al. (2017) describe QC methods. All samples were measured in duplicate, and extreme outliers were excluded. Urinary dilution was addressed by using creatinine-adjusted levels.
    - Direction/magnitude of effect: N/A
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Behaviors associated with ADHD were assessed using the Spanish version of Conners’ Rating Scales-Revised, which has been validated for the evaluation of ADHD. Mothers completed the CRS-R at the same follow-up visit in which the child completed the CPT-II tests. All tests were applied under the supervision of an experienced psychologist (++ for methods). Use of only parent reports and not teacher reports was noted by the authors as a study limitation because there is considerable variation between the two sources in terms of identifying ADHD-associated behaviors. Blinding was not reported, but it is unlikely that the mothers were aware of their urinary fluoride levels. Although mothers may have had knowledge that they were receiving fluoride through fluoridated salt or naturally occurring fluoride in their water, they would not have knowledge that this was relevant to the study purpose as the ADHD tests were conducted for the original cohort (as was acknowledged by the study authors in the discussion) (++ for blinding). Overall rating = ++.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]:
    - Statistical analyses: Bivariate analyses included Chi-square tests for categorical variables and ANOVA for continuous outcomes. Appropriate univariate statistics and transformations were performed before bivariate analyses. Residuals from fully adjusted linear regressions were checked and suggested skewness. Gamma regression with an identity link was used to examine the adjusted association between prenatal fluoride and each neurobehavioral outcome (instead of using log transformation). Generalized additive models were used to visually examine potential non-linearity. Sensitivity analyses examined impact of other covariates. Diagnostics tests were used to assess violations of the model assumptions and to identify remaining influential observations. The Benjamini-Hochberg false discovery rate (FDR) procedure was used to correct for multiple testing.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely or probably low risk-of-bias ratings in confounding, exposure, and outcome. Study strengths include individual exposure assessment measurements, blinding of outcome assessor to participants’ fluoride exposure, and the prospective cohort study design.

### E.2.4 Choi et al. (2015)

#### E.2.4.1 Study Details

- Study design: Cross-sectional
- Population: First-grade children (ages 6–8 years)
- Study area: Mianning County in southern Sichuan, China
- Sample size: 51 first-grade children
- Data relevant to the review: Adjusted associations between urine or drinking water fluoride levels and learning, memory, visual motor ability, motor ability, and manual dexterity. Study also had information based on dental fluorosis score.
- Reported association with fluoride exposure: No: None of the outcomes were significantly associated with fluoride exposure.

#### E.2.4.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Subjects were selected during the same time frame using the same methods. Fifty-one first-grade children residing in Mianning County in southern Sichuan, China were included in this pilot study. It is not specified whether the 51 children represented all first-grade children from this area or whether some refused to participate. Children who did not speak Chinese, were not students at the Primary School of Sunshui Village in Mianning County, or those with chronic or acute disease that might affect neurobehavioral function tests were excluded. Demographic characteristics are presented in Table 1 of the study, which indicates that subjects were similar. Covariates were adjusted for in the statistical analyses.
  - [underlined: Basis for Rating]: Definitely low risk of bias based on direct evidence that the exposure groups were similar and were recruited within the same time frame using the same methods with no evidence of differences in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The parents or guardians completed a questionnaire on demographic and personal characteristics of the children (sex, age at testing, parity, illnesses before age 3, and past medical history) and caretakers (age, parity, education and occupational histories, residential history, and household income). A 20-μL capillary blood sample was collected at the school by a Mianning County Center for Disease Control (CDC) health practitioner and tested for possible iron deficiency, which could be used as a covariate of neurodevelopmental performance. Covariates that were not assessed include maternal BMI, parental mental health, maternal smoking status, maternal reproductive factors, parental IQ, and HOME score. However, the study authors noted that confounding bias appeared to be limited due to the minimal diversity in the social characteristics of the subjects. The study authors indicated that CDC records documented that levels of other contaminants, including arsenic and lead, were very low in the area. Iodine differences were not specifically addressed, but there is no indication from the information provided that this might have been a concern.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias because there is direct evidence that the key covariates were considered and indirect evidence that co-exposure to arsenic was likely not an issue in this area and that methods used for collecting the information were valid and reliable.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The majority of results were reported for the 51 children stated to be included in the pilot study. In Table 5 of the study, the N for each dental fluorosis category totals only 43, but the text indicates 8 children did not have a Dean Index because permanent teeth had not erupted.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study used three different measurements of fluoride exposure: well water fluoride concentrations from the residence during pregnancy and onwards, fluoride concentrations from children’s first morning urine samples, and degree of children’s dental fluorosis. Fluoride concentrations in community well water were measured and recorded by Mianning County CDC; specific methods were not reported, but standard methods were likely used because analyses were conducted by the CDC and were likely the same as those used to measure the fluoride in urine. Migration of subjects was noted to be limited. Well water fluoride concentrations of the mother’s residence during pregnancy and onward were used to characterize a child’s lifetime exposure. To provide a measure of the accumulated body burden, each child was given a 330-mL (11.2-oz) bottle of Robust© distilled water (free from fluoride and other contaminants) to drink the night before the clinical examinations, after emptying the bladder and before bedtime. The first urine sample was collected at home the following morning, and the fluoride concentration was determined on a 5-mL sample using an ion-specific electrode at the Mianning CDC. There is no indication that urinary fluoride levels accounted for dilution, nor was it clear that the method of administering water to the children and collection methods sufficiently controlled for differences in dilution. One of the investigators, a dentist, performed a blinded dental examination on each child’s permanent teeth to rate the degree of dental fluorosis using the Dean Index. The Dean Index is commonly used in epidemiological studies and remains the gold standard in the dentistry armamentarium. The Index has the following classifications: normal, questionable, very mild, mild, moderate, and severe. Quality control (QC) procedures are not reported but were likely appropriate.
    - Direction/magnitude of effect size: Current levels were used to assess lifetime exposure. This is likely to be a non-differential exposure misclassification, and direction of bias is unknown. Because subject migration appears to be limited, it is likely that the current fluoride levels are adequate reflections of past exposure. Dental fluorosis would be an indicator that exposure occurred in the past, and there was a fair correlation between degree of dental fluorosis and current urine and water fluoride levels, with both increasing with increasing levels of dental fluorosis.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measure exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study authors adopted culture-independent tests considered feasible for children aged 6 to 8 years. The Wide Range Assessment of Memory and Learning (WRAML) was used for the assessment of memory and learning. Three subtests were also used. The Finger Windows subtest assesses sequential visual memory. The Design Memory subtest assesses the ability to reproduce designs from memory following a brief exposure. The Visual Learning subtest assesses the ability to learn the locations of pictured objects over repeated exposures. The Wechsler Intelligence Scale for Children-Revised (WISC-IV) included digit span for auditory span and working memory and block design for visual organization and reasoning. The grooved pegboard test assesses manual dexterity. The tests used have been validated on a Western population. Although there is no information provided to indicate that the tests were validated on the study population, the study authors indicated that the tests were culture-independent (+ for methods). Blinding of the outcome assessors or steps to minimize potential bias was not reported. However, it is unlikely that the assessors had knowledge of the individual exposure as children all came from the same area, and water and urine levels were tested at the CDC (+ for blinding). Overall = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that all outcomes were assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses were appropriate. Multiple regression models evaluated the associations between exposure indicators and test scores after adjusting for covariates. Specific regression models are not described or referenced, just stated to be “standard regression analysis with confounder adjustment.” The distributions of fluoride concentrations in urine and water were skewed and were log10-transformed to approximate a Gaussian distribution (test not specified). Results were reported as adjusted regression slopes and 95% CIs. There was no evidence that residual diagnostics were used to examine model assumptions; however, the impact on the effect estimates is expected to be minimal.
    - Other potential concerns: It should be noted that this study was a pilot study and, therefore, had a relatively small sample size (i.e., 51 children).
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in the confounding, exposure, and outcome domains. Study strengths include individual exposure assessment measurements with blinding at outcome assessment likely. All key covariates and many other covariates were considered in the study design or analysis.

### E.2.5 Li et al. (2004) [translated in Li et al. 2008a]

#### E.2.5.1 Study Details

- Study design: Cross-sectional
- Population: Full-term, normal neonates 24–72 hours old from healthy mothers
- Study area: Zhaozhou County, Heilongiang Province, China
- Sample size: 91 neonates (46 males and 45 females)
- Data relevant to the review: Comparison of neurobehavioral capacity between children in the high-fluoride area compared to the control area.
- Reported association with fluoride exposure: Yes: Significant differences in neurobehavioral assessment total scores between high-fluoride (36.48 ± 1.09) and control (38.28 ± 1.10) groups; significant differences in total neurobehavioral capacity scores as measured by non-biological visual orientation reaction and biological visual and auditory orientation reaction between the two groups (11.34 ± 0.56 in controls compared to 10.05 ± 0.94 in high-fluoride group).

#### E.2.5.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: There is indirect evidence that the exposure groups were similar. Participants were recruited during the same time frame using the same methods. From 2002 to 2003, 273 neonates were born in a hospital in Zhaozhou County, China. Ninety-one of 273 full-term neonates (46 males, 45 females) were randomly selected. Mothers ranged in age from 20 to 31 years, met multiple health criteria, and had not changed residence during pregnancy. Authors report that the two study groups were located in the same area with similar climate, living habits, economic and nutritional conditions, and cultural backgrounds, but do not provide these data in the manuscript. There is no statistically significant difference in the mode of delivery, birth weight, infant length, or sex. Subjects were separated into exposure groups after random selection.
  - [underlined: Basis for Rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited within the same time frame using the same methods with no evidence of differences in participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: No covariates were specifically considered in the analysis. The study authors note similarities in characteristics in the two populations (i.e., living habits, economic and nutritional conditions, and cultural backgrounds) but do not provide these data nor do they indicate which specific characteristics were considered. There were no significant differences in infant sex, birth method, gestational age, or infant weight and length. All tests were conducted when children were 1–3 days old. No potential co-exposures were discussed. Although arsenic is considered a potential issue in China, water quality maps indicate that there is a 25%–50% probability that the drinking water in that area exceeds the WHO guideline for arsenic of 10 µg/L.
  - [underlined: Potentially important study-specific covariates]: Key covariates, including age, sex, and measures of socioeconomic status (SES), were similar between exposure groups; however, arsenic was not considered. Arsenic often occurs in the drinking water along with fluoride in some Chinese populations; however, based on water quality maps, arsenic does not appear to be an issue in Zhaozhou County of the Heilongjiang Province. Iodine deficiencies are not mentioned.
    - Direction/magnitude of effect size: Conceptually, the presence of arsenic would potentially bias the association away from the null if it were present with fluoride. Deficiencies in iodine would potentially bias the association away from the null if it were present in areas of higher fluoride but toward the null if it were present in areas of lower fluoride. Neither of these are considered a concern in this study for reasons detailed above.
  - Basis for rating: Probably low risk of bias based on indirect evidence that the key covariates were considered, co-exposure to arsenic was likely not an issue in this area, and methods used for collecting the information were valid and reliable.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Although authors did not discuss why only 91 of the 273 neonates available were randomly selected, results were available for all 91 subjects.
  - [underlined: Basis for rating]: Definitely low risk of bias based on results being available for all subjects.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were split into control and high-fluoride groups based on fluoride levels in their places of residence. Although the levels were provided (1.7–6.0 mg/L for the high-fluoride group compared to 0.5–1.0 mg/L for the control group), it was not reported how or when these levels were measured. Urine was collected when women were hospitalized but before labor began. Urine samples were sent to a specific lab for measurement using fluoride ion-selective electrode. It was noted that this procedure strictly followed the internal controls of the laboratory, indicating quality control. Level of detection (LOD) was not provided. Urinary fluoride levels were significantly higher in the high-fluoride mothers (3.58 ± 1.47 mg/L) compared to the control-group mothers (1.74 ± 0.96 mg/L). There was indirect evidence that exposure was consistently assessed using well-established methods that directly measure exposure. Although results were mainly based on exposure area, they were supported by urine data, making exposure misclassification less of a concern.
    - Direction/magnitude of effect size: There is high variability in both water fluoride and urine fluoride in the subjects from the high-exposure area. Although there is no overlap in the water fluoride levels in the exposure areas, there is some overlap in the urine concentrations in the mothers from the two areas. This may reflect the single measurement and pose no specific bias, or it could indicate that some mothers in the high-fluoride area have lower fluoride exposure, which could bias the association toward the null.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measure exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: A standard neonatal behavioral neurological assessment method was carried out by professionals in the pediatric department working in a neonatal section trained specifically for these programs and passing the training exams (+ for methods). The examinations were carried out 1 to 3 days after delivery. Because urine samples were collected on the day of delivery and sent to a separate laboratory, it is likely that the outcome assessors were blind. Although the subjects were separated by fluoride exposure area, it is not likely that the professionals were aware of the exposure as the tests were conducted in the hospital (+ for blinding).
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessors were blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: The study authors reported numerous outcomes in sufficient detail; however, because a list of outcomes tested was not provided, there is no direct evidence that all were reported.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that all the study’s measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses are described only as a t-test. Consideration of heterogeneity of variance was not reported. Results are reported as mean and standard deviations of neurological scores. Maternal urinary fluoride levels were used only to compare exposures between exposed and control groups. Infants in the control group were from four villages, and those in the exposed group were from five villages within the same district. Infants were randomly selected before they were assigned to exposed or control groups. In the comparisons, there was no accounting for clustering at the village level. It is likely that the standard error of the difference in mean neurobehavioral assessment scores between the high fluoride group and control group will be biased, making differences appear stronger than they actually are. However, the use of multiple villages per exposure group is likely to mitigate some of the impact of this lack of accounting for clustering, and the overall impact on effect estimates is expected to be minimal.
    - Other potential concerns: It should be noted that although the study states that subjects were randomly selected, it is unclear why only 91 subjects were included and whether they were randomly selected to obtain equal numbers in the high-fluoride and control groups.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that statistical analyses were appropriate and that there were no other potential threats of risk of bias.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in the confounding, exposure, and outcome domains. Study strengths include individual exposure assessment measurements to support the differences in the two areas. Tests were noted to be conducted at the hospital, providing indirect evidence that blinding was not a concern during the outcome evaluation. Although there was some potential for bias due to the lack of accounting for arsenic or iodine deficiencies, co-exposure to arsenic was likely not a major concern according to groundwater quality maps.

### E.2.6 Riddell et al. (2019)

#### E.2.6.1 Study Details

- Study design: Cross-sectional
- Population: Canadian Health Measures Survey (Cycles 2 and 3) participants (children aged 6–17 years)
- Study area: General population, Canada
- Sample size: 3,745 children
- Data relevant to the review: Adjusted associations between water and urinary fluoride and risk of ADHD and attention symptoms by water fluoride in the tap water or community fluoridation status.
- Reported association with fluoride exposure: Yes: Significant positive association between tap water fluoride and risk of ADHD diagnosis (adjusted OR = 6.10 per 1-mg/L increase; 95% CI: 1.60, 22.8) and hyperactivity/inattentive symptoms (adjusted β = 0.31 per 1-mg/L increase; 95% CI: 0.04, 0.58). Significant positive association between community water fluoridation status and risk of ADHD diagnosis (adjusted OR = 1.21 comparing fluoridated with non-fluoridated areas; 95% CI: 1.03, 1.42) and hyperactivity/inattentive symptoms (adjusted β = 0.11; 95% CI: 0.02, 0.58). No significant associations with urinary fluoride levels.

#### E.2.6.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Subjects were part of Cycles 2 and 3 of the Canadian Health Measures Survey. This is a nationally representative sample of residents living in 10 provinces. Specific inclusion criteria were provided. This study was restricted to children 6–17 years of age with different fluoride measurements that consisted of three participant samples. One of the samples was available only in Cycle 3.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the exposed groups were similar and were recruited with the same methods during the same time frame.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Covariates included in all models included age at testing, sex, ethnicity, BMI, parents’ education, total household income, exposure to cigarette smoke inside the home, and log-transformed concurrent blood lead levels. Covariates such as parental behavioral and mental health disorders, quantity and quality of caregiving environment, and co-exposure to arsenic were not discussed. The study used data from the Canadian Health Measures Survey, which consists of a nationally representative sample of Canadians. Most Canadians (~89%) receive water from municipal water supplies, which monitor for levels of arsenic. Therefore, co-exposure to arsenic is not likely an issue in this population. Rationale for selection of covariates was based on relationship to ADHD diagnosis and to fluoride metabolism based on literature review and consultation with an ADHD expert. There is no information of the source of data for covariates, but it is likely the questionnaires from the Canadian Health Measures Survey, which are considered standardized and validated.
  - [underlined: Potentially important study-specific covariates]: All key covariates were considered in this study.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Probably low risk of bias because there is indirect evidence that the key covariates were considered, co-exposure to arsenic was likely not an issue, and methods used for collecting the information were valid and reliable.
- Attrition:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: There is no information indicating that there were any data excluded due to missing covariates. All exclusions of children were described and reasonable (i.e., drinking bottled water when considering city fluoridation as a measure of fluoride exposure). Outliers were stated to be excluded, but methods for determining this were provided, and it was noted that the outliers were 0.27% of the values.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Urinary Fluoride: Spot urine samples were collected under normal non-fasting conditions and analyzed using an Orion pH meter with a fluoride ion-selective electrode after being diluted with an ionic adjustment buffer. Analysis was performed at the Human Toxicology Laboratory of the Institut National de Santé Publique du Québec. The precision and accuracy of the fluoride analyses, including quality control and quality assurance, were described by Health Canada (2015). The limits of detection were 20 µg/L for Cycle 2 and 10 µg/L for Cycle 3 with no values below detection. Fluoride levels were adjusted for specific gravity.
    Water Fluoride in Tap Water: Tap water was collected at the subjects’ homes in Cycle 3 only. Samples were analyzed for fluoride concentrations using anion exchange chromatography procedure with an LOD of 0.006 mg/L. Values below the LOD were imputed with LOD/square root(2). Of the 980 samples, 150 (15%) were below detection.
    Chlorinated Water Fluoride Status: This was determined by viewing reports on each city’s website or contacting the water treatment plant (provided in supplemental material). Children were excluded if they drank bottled water, had a well, had a home filtration system, lived in the current residence for 2 years or less, or lived in an area with mixed city fluoridation.
    - Direction/magnitude of effect size: There is not any specific impact on the direction or magnitude of effect size expected. Urinary fluoride levels are reflective of a recent exposure, but the study authors adjusted to account for dilution. The possibility of exposure misclassification would be similar in all subjects and would be non-differential. There is less potential for exposure misclassification due to tap water or chlorinated water fluoride status, since children who drank bottled water were excluded and children who had a home filtration system were excluded from the chlorinated water status.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]:
    Strengths and Difficulties Questionnaire (SDQ): The questionnaire was administered to youths under 18 years. Children aged 6–11 years had SDQ ratings provided by parents and guardians, but youths aged 12–17 years completed the questionnaire themselves. Tests consist of 25 items with a 3-point scale. Items were divided into five subscales: emotional problems, conduct problems, hyperactivity-inattention, peer problems, and prosocial behavior. The current study used only the hyperactivity-inattention subscale. Validation of this method was not reported (− for methods).
    ADHD: Ninety percent of youths with ADHD are diagnosed after age 6. For children aged 6–11 years, ADHD diagnosis was provided by parents, but youths aged 12–17 years completed the questionnaire themselves. Cycle 2 asked “Do you have a learning disability?”; if the subject answered “yes,” he/she was asked to specify the type (four options were available and described). In Cycle 3, parents were asked directly whether they had ADHD, and children 12 years and older were asked whether they had a physician diagnosis of ADHD and, if so, what subtype (− for methods because different methods were used, and only the children 12 years and older in Cycle 3 were asked specifically about a doctor’s diagnosis). Both were measured in both cycles. Blinding is likely not an issue as subjects would not have knowledge of the urine or tap water fluoride levels. However, they would likely have knowledge of the city.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that the outcome was assessed using insensitive methods that varied based subject age.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods sections were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Robust logistic regression was used to examine the association between fluoride exposure and ADHD diagnosis, adjusting for covariates. Box-Tidewell tests were used to check the linearity of the relationship with the continuous predictors. Linear regression was used for the SDQ scores using Huber-White standard errors. Multicollinearity was evaluated using variance inflation factor (VIF) statistics. Outliers with high studentized residuals, high leverage, or large Cook’s distance values were removed from all analyses with urinary fluoride. All regressions were tested for interactions between fluoride exposure and age and between fluoride exposure and sex. Sensitivity analyses were conducted to test the different survey cycles. There is no mention of adjustment for the complex survey design using survey weights or bootstrapped weights to ensure appropriate calculation of the estimated variances; however, the overall impact on effect estimates is expected to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding and exposure. Study strengths include individual exposure assessment measurements and the addressing of key covariates but were limited by the cross-sectional study design and insensitive outcome measures.

### E.2.7 Rocha-Amador et al. (2009)

#### E.2.7.1 Study Details

- Study design: Cross-sectional
- Population: Children aged 6–11 years
- Study area: Durango, Mexico
- Sample size: 80 children
- Data relevant to the review: Associations between urinary fluoride levels and visuospatial organization and visual memory (using the Rey-Osterrieth Complex Figure Test, children’s version).
- Reported association with fluoride exposure: Yes: Significant inverse correlations between urinary fluoride and visuospatial organization (r = −0.29) and visual memory (r = −0.27) scores. No significant correlations with urinary arsenic.

#### E.2.7.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were from the same population and were recruited during the same time frame using the same methods. Although this study compared three sites with antecedents of environmental pollution to mixtures of either F-As, Pb-As, or DDT-PCBs, authors evaluated each contaminant separately. The only area of interest with F and As contamination is in Durango state (5 de Febrero) where drinking water is polluted naturally with F and As at levels exceeding 6 and 19 times, respectively, the World Health Organization (WHO) limits (WHO 2008). Children attending public schools were screened through personal interviews for study eligibility. Inclusion criteria were children between 6 and 11 years old, living in the study area since birth, whose parents signed the agreement to participate. Children with a neurological disease diagnosed by a physician and reported by the mother were excluded from the study. The final sample for the F-As group was 80. Participation rates were not reported. Selected demographic characteristics are presented in Table 1 of the study.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the populations were similar and recruited during the same time frame using the same methods.
- Confounding:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: Covariates included blood lead (PbB), age, sex, and height-for-age z-scores; only age had significant associations and was included in the final analysis. Arsenic was also assessed and analyzed separately from fluoride. Arsenic in urine was analyzed by atomic absorption spectrophotometer coupled to a hydride system (Perkin-Elmer model AAnalyst 100). Although the model did not adjust for arsenic, arsenic in the F-As group was not associated with either outcome; therefore, arsenic co-exposure is not considered a major concern in this study. PbB was analyzed with a Perkin-Elmer 3110 atomic absorption spectrophotometer using a graphite furnace. Authors note that the mean blood lead level in the F-As study area was 5.2 µg/dL, and 8% of the children had values above the reference value of 10 µg/dL. PbB was stated not to affect results and was not included in the final analysis. Other covariate data were obtained during the study interview. Father’s education was provided and, in the F-As group, was stated to range from 0–16 years, but this was not considered. Maternal education, smoking, and SES were also not considered. The authors provide an SES score of 5.9 ± 1.4 for the 5 de Febrero region (the fluoride region). It is not clear whether this would vary by fluoride or arsenic levels.
  - [underlined: Potentially important study-specific covariates]: SES.
    - Direction/magnitude of effect size: There are insufficient data to determine the impact on the magnitude or direction of effect size. The impact on the direction of the association would likely depend on the association between fluoride exposure and SES.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that the SES was not considered in the study design or analysis and may have varied by fluoride levels.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Data are complete. All 80 participants stated to be the final sample for the site of interest (F-As) were included in all analyses.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that there was no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Fluoride in urine (FU) was analyzed according to method 8308 (“fluoride in urine”) from the National Institute for Occupational Safety and Health (NIOSH 1984) with a sensitive specific ion electrode. As a quality control check, reference standard “fluoride in freeze dried urine” (NIST SRM 2671a) was analyzed. The accuracy was 97.0% ± 6.0%. Levels of FU and AsU were adjusted for urinary creatinine, which was analyzed by a colorimetric method (Bayer Diagnostic Kit, Sera-Pak1 Plus). However, details on the collection methods were not reported.
    - Direction/magnitude of effect size: Spot urine samples in a small sample size (i.e., 80 children) may have some exposure misclassification. Adjusting for dilution reduces the potential for misclassification based on differences in dilution. Exposure misclassification would likely be non-differential.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: IQ was assessed through the Rey-Osterrieth Complex Figure Test (ROCF). This is a less well-established method, although the authors provide citations suggesting it has been validated and standardized for the Mexican population (+ for methods). According to the study report, the neuropsychologist who administered the test was blinded to all exposure types and levels (++ for blinding). Overall rating for methods and blinding = +.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods were reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses used log-transformed exposure variables (although rationale was not provided). Crude and partial correlations were calculated to evaluate associations between serum fluoride levels and TOCF scores. There is no other description of the regression model, and regression diagnostics to evaluate model assumptions are not presented; however, the overall impact on effect estimates is expected to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in exposure and outcome. Study strengths include individual exposure assessment measurements and blinding of outcome assessor to participants’ fluoride exposure, but it is limited by the cross-sectional study design, lack of consideration of SES in the study population, co-exposure with arsenic, and use of spot samples in a small population.

### E.2.8 Valdez Jiménez et al. (2017)

#### E.2.8.1 Study Details

- Study design: Prospective cohort
- Population: Infants aged 3–15 months
- Study area: Durango City and Lagos de Moreno, Jalisco, Mexico
- Sample size: 65 infants
- Data relevant to the review: The Bayley Scales of Infant Development II was used to assess Mental Development Index scale and the Psychomotor Development Index scale in children aged 3 to 15 months and evaluated for associations with first and second trimester maternal urine fluoride.
- Reported association with fluoride exposure: Yes: Significant association between maternal urinary fluoride and MDI score during first trimester (adjusted β = −19.05 per log10-mg/L increase; SE = 8.9) and second trimester (adjusted β = −19.34 per log10-mg/L increase; SE = 7.46). No association between maternal fluoride during any trimester and Psychomotor Developmental Index (PDI).

#### E.2.8.2 Risk of Bias

- Author contacts:
  - Authors were not contacted for additional information because it was not necessary.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were recruited from two endemic areas in Mexico. The study authors do not provide information on the similarities or differences between the two areas, nor do they indicate whether there were different participation rates. However, recruitment methods were the same. Women receiving prenatal care in health centers located in Durango City and Lagos de Moreno, Jalisco, Mexico were recruited in 2013–2014. Participation rates are not likely to be an issue as characteristics were similar between those who participated and those who did not. Although the authors did not provide characteristics by area, the characteristics provided do not indicate any differences that may be biased by the selection. Considering the age range for the non-participants, the mean age for non-participants appears to be incorrect (or the age range is incorrect); however, there does not appear to be a difference that would potentially indicate selection bias.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposure groups were similar and were recruited with the same methods in the same time frame, with no evidence of differences or issues with participation/response rates.
- Confounding:
  - [underlined: Rating]: Probably high risk of bias (−)
  - [underlined: Summary]: Questionnaires were used to obtain information about sociodemographic factors, prenatal history, mother’s health status before pregnancy (e.g., use of drugs, vaccines, diseases), and the type of water for drinking and cooking. The marginalization index (MI) was obtained from the National Population Council (CONAPO). Two additional surveys were conducted during the second and third trimester of pregnancy to get information about the mother’s health, pregnancy evolution, and sources of water consumption. A survey was also conducted to get information about childbirth (type of birth, week of birth, weight and length of the baby at birth, Apgar score and health conditions of the baby during the first month of life). This information was corroborated with the birth certificate. Linear regression models included gestational age, children’s age, marginality index, and type of drinking water. Bivariate analyses were conducted on the other factors, including sex, prior to conducting multivariable regression models. Some important covariates were not considered, including parental mental health, IQ, smoking, and potential co-exposures. Water quality maps indicate a potential for arsenic to be present in the study area.
  - [underlined: Potentially important study-specific covariates]: Arsenic is a potential co-exposure in this area of Mexico.
    - Direction/magnitude of effect size: If arsenic were present as a co-exposure, it would likely bias the association away from the null.
  - [underlined: Basis for rating]: Probably high risk of bias based on indirect evidence that there is a potential for co-exposure with arsenic that was not addressed.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Out of the 90 women selected for inclusion in the study, 65 approved the participation of their infants. The authors provide a table of characteristics between women who consented to their children’s cognitive evaluation and those who participated only in biological monitoring. There were no significant differences between the groups. There were fewer women who provided urine during the second and third trimesters. All specified children are included in the relevant analyses.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exclusion of subjects from analyses was adequately addressed, and reasons were documented when subjects were removed from the study or excluded from analyses.
- Exposure:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Fluoride exposure was assessed through morning urine samples and water fluoride levels collected from the children’s homes. Sampling methodology was appropriately documented, and water levels were quantified through specific ion-sensitive electrode assays. QC was described, and accuracy was >90%. Urinary fluoride was corrected by specific gravity.
    - Direction/magnitude of effect size: Not applicable.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that exposure was consistently assessed using well-established methods that directly measured exposure.
- Outcome:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Neurodevelopment was assessed with the Bayley Scales of Infant Development II (BSDI-II) that was noted to be reliable and valid for evaluating children from 3 months to 5 years of age. The average age of children assessed was 8 months, with a range of 3–15 months) (++ for methods). The study report stated that a trained psychologist who was blinded to the mother’s fluoride exposure evaluated the infants at home (++ for blinding). Overall rating for methods and blinding = ++.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that the outcome was assessed using instruments that were valid and reliable in the study population, and that the outcome assessor was blind to participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: All outcomes outlined in the abstract, introduction, and methods were reported. Table 4 of the study displays only data for trimesters 1 and 2. Although third trimester data were collected, they were not reported, likely because they were available for only 29 subjects. No discussion of this was provided.
  - [underlined: Basis for rating]: Probably low risk of bias because, although it appears some data were not reported, it is likely because there were insufficient data and not because the authors were selectively reporting the results.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Statistical analyses used log10-transformed exposure variables. Normality, homoscedasticity, and linearity assumptions were tested and satisfied for MDI and PDI scores. Bivariate analyses included correlations, t-tests, and ANOVA. Multiple linear regression models by the first and second trimester of pregnancy were used to evaluate the association between maternal fluoride exposure and MDI and PDI scores. The best-fit model was selected using a “stepwise method,” and the best-fit line was evaluated using “the curve fitting method.” It is not further specified or cited what these methods entailed. Best-fit or goodness-of-fit statistics are not reported. It is unclear how a best-fit model could be selected when the authors state that all models adjusted for the same set of covariates regardless of significance, and these covariates also appear in the final model—presumably the best-fit model. It is unlikely that a stepwise method would retain all those covariates unless they were forced in the model. Residual analysis was conducted to assess model validity; however, there is no description of the results of the residual analysis. Nonetheless, the impact on effect estimates is expected to be minimal.
    - Other potential concerns: No other potential concerns were identified. In the peer-review report, NASEM (2020) cited the following as potential concerns: “the large difference in numbers of males and females in the offspring (20 males, 45 females), and apparently incorrect probabilities were reported for age differences between participants and nonparticipants, high rates of cesarean deliveries and premature births among participants (degree of overlap not reported), and incorrect comparisons of observed prematurity rates with national expected rates.” However, these concerns were taken into consideration in other domains (Selection, Confounding).
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and there were no other potential threats of risk of bias identified.
- Basis for classification as low risk-of-bias study overall: Definitely low risk-of-bias ratings in exposure and outcome. Study strengths include individual exposure assessment measurements and blinding of outcome assessor to participants’ fluoride exposure, but it is limited by the cross-sectional study design and lack of accounting for potential co-exposures to arsenic.

### E.2.9 Wang et al. (2020a)

#### E.2.9.1 Study Details

- Study design: Cross-sectional
- Population: School children aged 7–13 years
- Study area: Tongxu County, China
- Sample size: 325 school children
- Data relevant to the review: Adjusted associations between urine fluoride concentrations and ADHD and other measures of learning disability.
- Reported association with fluoride exposure: Yes: Significant positive association between urinary fluoride and psychosomatic problems (adjusted β = 4.01 per 1-mg/L increase; 95% CI: 2.74, 5.28) and increased risk of a T-score >70 (adjusted OR = 1.97 per 1-mg/L increase; 95% CI: 1.19, 3.27). No significant associations with ADHD or other measures of learning disability.

#### E.2.9.2 Risk of Bias

- Author contacts:
  - Authors were contacted in July of 2020 to obtain additional information for risk-of-bias evaluation. No response was received.
- Population selection:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Subjects were recruited in 2017 from Tongxu County, China. Children were selected from four randomly selected primary schools in the area. Selection was based on specified inclusion rules. It was noted that the living habits and diets of the participants from the four schools were well matched, but details were not provided. The area did not have industrial pollution within 1 km of the living environment of the children, and it was noted that the children were not exposed to other neurodevelopmental toxicants (lead, cadmium, arsenic, or mercury). A table of subject characteristics was provided in the study but not by school or exposure. This was a pilot study, and it was not explicitly stated whether all eligible subjects participated in the study. There is no information on participation rates or whether they varied by school.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the exposed groups were recruited using similar methods during the same time frame and that any differences between the exposed groups were considered in the statistical analyses.
- Confounding:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: It was noted that subjects were well matched in terms of living habits and diets, but there were no specifics provided. It was noted that there was no industrial exposure or exposure to other neurotoxins such as lead, cadmium, arsenic, or mercury. Covariates were collected using a standardized and structured questionnaire completed by the children and their guardians under the direction of investigators, but reliability or validity of the questionnaire was not reported. Information collected included age, sex, weight, height, parental education level, and parental migration (or work as migrant workers). IQ scores evaluated by the Combined Raven’s Test–the Rural in China were used to represent basic cognitive function. Models were adjusted for age, BMI, sex, mother and father migration, and urinary creatinine. Adjustments were not made for parental education, race/ethnicity, maternal demographics (e.g., maternal age, BMI), parental behavioral and mental health disorders (e.g., ADHD, depression), smoking (e.g., maternal smoking status, secondhand tobacco smoke exposure), reproductive factors (e.g., parity), iodine deficiency/excess, maternal (and paternal) IQ, quantity and quality of caregiving environment (e.g., HOME score), or SES other than parental migration. There is no evidence to suggest that SES would differ substantially among the four rural schools in the same area of China that were randomly selected.
  - [underlined: Potentially important study-specific covariates]: SES.
    - Direction/magnitude of effect size: The impact on the direction and magnitude of effect size are unknown. It was noted that the subjects were matched in terms of living habits and diet, and this could be an indication that SES was not different among the groups, but details were not provided.
  - [underlined: Basis for rating]: Probably low risk of bias because there is indirect evidence that the key covariates were considered, that the methods for collecting the information were valid and reliable, and that co-exposure to arsenic was not an issue in this area.
- Attrition:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: Data are complete. It was noted that there were 325 subjects included, and results were available on all subjects.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that there was no attrition.
- Exposure:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]: Spot urine samples were collected from each child in the early morning into cleaned polyethylene tubes. Fluoride concentrations were measured using fluoride ion-selective electrode [with reference to Ma et al. (2017); however, that reference cites Zhou et al. (2012)]. Therefore, no QC methods or LODs were available. Fluoride concentrations were creatinine-adjusted.
    - Direction/magnitude of effect size: Spot urine samples account for only recent exposure. Although this could cause some exposure misclassification, the number of subjects should help dilute any issues with the non-differential misclassification.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that exposure was consistently assessed using acceptable methods that provide individual levels of exposure.
- Outcome:
  - [underlined: Rating]: Probably high risk of bias (NR)
  - [underlined: Summary]: Children’s behavior was assessed by the Chinese version of Conners’ Parent Rating Scale-Revised (CPRS-48). The homogeneity reliability of Cronbach α in the Chinese version of CPRS-48 was 0.932, the correlation of Spearman-brown split-half was 0.900, and the retest reliability of total score was 0.594. Raw scores for each subscale were converted into sex- and age-adjusted T-scores within a mean ± standard deviation (SD) of 50 ± 10. The guardians independently completed the CPRS-48 according to the instruction manual under the direction of trained investigators (++ for methods). Blinding is not reported. Although it is unlikely that the outcome assessors were aware of the fluoride levels in the urine, it is unclear whether subjects were selected based on areas with endemic fluoride or whether parents were aware of fluoride concentrations in the areas (NR for blinding). Overall rating for methods and blinding = NR.
  - [underlined: Basis for rating]: Probably high risk of bias based on no information provided to indicate that the outcome assessors were blind to the participants’ fluoride exposure.
- Selective Reporting:
  - [underlined: Rating]: Definitely low risk of bias (++)
  - [underlined: Summary]: All outcomes in the abstract, introduction, and methods are reported in sufficient detail.
  - [underlined: Basis for rating]: Definitely low risk of bias based on direct evidence that all measured outcomes were reported.
- Other potential threats:
  - [underlined: Rating]: Probably low risk of bias (+)
  - [underlined: Summary]:
    - Statistical analyses: Multiple linear regression models were used to assess the association between urinary fluoride exposure and each behavioral outcome. Logistic regression was used to assess the risk of behavioral problems (T-scores >70) due to fluoride exposure. Sensitivity analyses were performed, with models adjusting for combinations of age, BMI, sex, mother migrated, father migrated, and urinary creatinine levels. Regression diagnostics to evaluate model assumptions are not described; however, the overall impact on effect estimates is expected to be minimal.
    - Other potential concerns: None identified.
  - [underlined: Basis for rating]: Probably low risk of bias based on indirect evidence that the statistical analyses were appropriate and no other potential threats of risk of bias were identified.
- Basis for classification as low risk-of-bias study overall: Probably low risk-of-bias ratings in confounding and exposure. Study strengths include individual exposure assessment measurements, but it is limited by the cross-sectional study design and lack of details on blinding of the outcome assessment. All key covariates were considered in the study design or analysis.