# Appendix D Risk-of-bias Figures

## D.1 Studies in Humans

Figure D-1

Risk-of-bias Heatmap for Low Risk-of-bias Human Neurodevelopmental or Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-1 and additional study details in HAWC here (https://hawcproject.org/summary/visual/524/) (NTP 2019).

Figure D-2

Risk-of-bias Bar Chart for Low Risk-of-bias Human Neurodevelopmental or Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-2 and additional study details in HAWC here (https://hawcproject.org/summary/visual/525/) (NTP 2019).

Figure D-3

Risk-of-bias Heatmap for High Risk-of-bias Human Neurodevelopmental or Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-3 and additional study details in HAWC here (https://hawcproject.org/summary/visual/526/) (NTP 2019).

Figure D-4

Risk-of-bias Bar Chart for High Risk-of-bias Human Neurodevelopmental or Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-4 and additional study details in HAWC here (https://hawcproject.org/summary/visual/527/) (NTP 2019).

Figure D-5

Risk-of-bias Heatmap for Low Risk-of-bias Children’s IQ Studies Following Fluoride Exposure

An interactive version of Figure D-5 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Lower-RoB-IQ-in-children/) (NTP 2019).

Figure D-6

Risk-of-bias Bar Chart for Low Risk-of-bias Children’s IQ Studies Following Fluoride Exposure

An interactive version of Figure D-6 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Figure_A3-06-Lower-RoB-IQ-in-children_bar/) (NTP 2019).

Figure D-7

Risk-of-bias Heatmap for High Risk-of-bias Children’s IQ Studies Following Fluoride Exposure

An interactive version of Figure D-7 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Higher-RoB-IQ-in-children/) (NTP 2019).

Figure D-8

Risk-of-bias Bar Chart for High Risk-of-bias Children’s IQ Studies Following Fluoride Exposure

An interactive version of Figure D-8 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Figure_A3-08-Higher-RoB-IQ-in-children_bar/) (NTP 2019).

Figure D-9

Risk-of-bias Heatmap for Low Risk-of-bias Children’s Other Neurodevelopmental Effect Studies Following Fluoride Exposure

An interactive version of Figure D-9 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Lower-RoB-Neurodevelopmental-Effects-in-children/) (NTP 2019).

Figure D-10

Risk-of-bias Bar Chart for Low Risk-of-bias Children’s Other Neurodevelopmental Effect Studies Following Fluoride Exposure

An interactive version of Figure D-10 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Figure_A3-10-Lower-RoB-Other-Neuro-in-children_bar/) (NTP 2019).

Figure D-11

Risk-of-bias Heatmap for High Risk-of-bias Children’s Other Neurodevelopmental Effect Studies Following Fluoride Exposure

An interactive version of Figure D-11 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Higher-RoB-Neurodevelopmental-Effects-in-children/) (NTP 2019).

Figure D-12

Risk-of-bias Bar Chart for High Risk-of-bias Children’s Other Neurodevelopmental Effect Studies Following Fluoride Exposure

An interactive version of Figure D-12 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Figure_A3-12-Higher-RoB-Other-Neuro-children_bar/) (NTP 2019).

Figure D-13

Risk-of-bias Heatmap for Low Risk-of-bias Adult Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-13 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Lower-RoB-Cognitive-in-adults/) (NTP 2019).

Figure D-14

Risk-of-bias Bar Chart for Low Risk-of-bias Adult Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-14 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Figure_A3-14-Lower-RoB-Cognitive-in-adults_bar/) (NTP 2019).

Figure D-15

Risk-of-bias Heatmap for High Risk-of-bias Adult Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-15 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Higher-RoB-Cognitive-in-adults/) (NTP 2019).

Figure D-16

Risk-of-bias Bar Chart for High Risk-of-bias Adult Cognitive Studies Following Fluoride Exposure

An interactive version of Figure D-16 and additional study details in HAWC here (https://hawcproject.org/summary/visual/assessment/405/Figure_A3-16-Higher-RoB-Cognitive-in-adults_bar/) (NTP 2019).

Figure D-17

Risk-of-bias Heatmap for Low Risk-of-bias Human Mechanistic Studies Following Fluoride Exposure

An interactive version of Figure D-17 and additional study details in HAWC here (https://hawcproject.org/summary/visual/598/) (NTP 2019).

Figure D-18

Risk-of-bias Bar Chart for Low Risk-of-bias Human Mechanistic Studies Following Fluoride Exposure

An interactive version of Figure D-18 and additional study details in HAWC here (https://hawcproject.org/summary/visual/599/) (NTP 2019).

Figure D-19

Risk-of-bias Heatmap for High Risk-of-bias Human Mechanistic Studies Following Fluoride Exposure

An interactive version of Figure D-19 and additional study details in HAWC here (https://hawcproject.org/summary/visual/600/) (NTP 2019).

Figure D-20

Risk-of-bias Bar Chart for High Risk-of-bias Human Mechanistic Studies Following Fluoride Exposure

An interactive version of Figure D-20 and additional study details in HAWC here (https://hawcproject.org/summary/visual/601/) (NTP 2019).

## D.2 Studies in Non-human Animals

Figure D-21

Risk-of-bias Heatmap for New Developmental Animal Learning and Memory Studies Following Fluoride Exposure

An interactive version of Figure D-21 and additional study details in HAWC here (https://hawcproject.org/summary/visual/530/) (NTP 2019).

Figure D-22

Risk-of-bias Bar Chart for New Developmental Animal Learning and Memory Studies Following Fluoride Exposure

An interactive version of Figure D-22 and additional study details in HAWC here (https://hawcproject.org/summary/visual/532/) (NTP 2019).

Figure D-23

Risk-of-bias Heatmap for New Adult Animal Learning and Memory Studies Following Fluoride Exposure

An interactive version of Figure D-23 and additional study details in HAWC here (https://hawcproject.org/summary/visual/531/) (NTP 2019).

Figure D-24

Risk-of-bias Bar Chart for New Adult Animal Learning and Memory Studies Following Fluoride Exposure

An interactive version of Figure D-24 and additional study details in HAWC here (https://hawcproject.org/summary/visual/533/) (NTP 2019).

Figure D-25

Risk-of-bias Heatmap for Low Risk-of-bias Animal Biochemical Studies Following Fluoride Exposure

An interactive version of Figure D-25 and additional study details in HAWC here (https://hawcproject.org/summary/visual/579/) (NTP 2019).

Figure D-26

Risk-of-bias Bar Chart for Low Risk-of-bias Animal Biochemical Studies Following Fluoride Exposure

An interactive version of Figure D-26 and additional study details in HAWC here (https://hawcproject.org/summary/visual/580/) (NTP 2019).

Figure D-27

Risk-of-bias Heatmap for High Risk-of-bias Animal Biochemical Studies Following Fluoride Exposure

An interactive version of Figure D-27 and additional study details in HAWC here (https://hawcproject.org/summary/visual/581/) (NTP 2019).

Figure D-28

Risk-of-bias Bar Chart for High Risk-of-bias Animal Biochemical Studies Following Fluoride Exposure

An interactive version of Figure D-28 and additional study details in HAWC here (https://hawcproject.org/summary/visual/582/) (NTP 2019).

Figure D-29

Risk-of-bias Heatmap for Low Risk-of-bias Animal Neurotransmission Studies Following Fluoride Exposure

An interactive version of Figure D-29 and additional study details in HAWC here (https://hawcproject.org/summary/visual/583/) (NTP 2019).

Figure D-30

Risk-of-bias Bar Chart for Low Risk-of-bias Animal Neurotransmission Studies Following Fluoride Exposure

An interactive version of Figure D-30 and additional study details in HAWC here (https://hawcproject.org/summary/visual/584/) (NTP 2019).

Figure D-31

Risk-of-bias Heatmap for High Risk-of-bias Animal Neurotransmission Studies Following Fluoride Exposure

An interactive version of Figure D-31 and additional study details in HAWC here (https://hawcproject.org/summary/visual/585/) (NTP 2019).

Figure D-32

Risk-of-bias Bar Chart for High Risk-of-bias Animal Neurotransmission Studies Following Fluoride Exposure

An interactive version of Figure D-32 and additional study details in HAWC here (https://hawcproject.org/summary/visual/586/) (NTP 2019).

Figure D-33

Risk-of-bias Heatmap for Low Risk-of-bias Animal Oxidative Stress Studies Following Fluoride Exposure

An interactive version of Figure D-33 and additional study details in HAWC here (https://hawcproject.org/summary/visual/587/) (NTP 2019).

Figure D-34

Risk-of-bias Bar Chart for Low Risk-of-bias Animal Oxidative Stress Studies Following Fluoride Exposure

An interactive version of Figure D-34 and additional study details in HAWC here (https://hawcproject.org/summary/visual/588/) (NTP 2019).

Figure D-35

Risk-of-bias Heatmap for High Risk-of-bias Animal Oxidative Stress Studies Following Fluoride Exposure

An interactive version of Figure D-35 and additional study details in HAWC here (https://hawcproject.org/summary/visual/589/) (NTP 2019).

Figure D-36

Risk-of-bias Bar Chart for High Risk-of-bias Animal Oxidative Stress Studies Following Fluoride Exposure

An interactive version of Figure D-36 and additional study details in HAWC here (https://hawcproject.org/summary/visual/590/) (NTP 2019).

Figure D-37

Risk-of-bias Heatmap for Low Risk-of-bias Animal Histopathology Studies Following Fluoride Exposure

An interactive version of Figure D-37 and additional study details in HAWC here (https://hawcproject.org/summary/visual/591/) (NTP 2019).

Figure D-38

Risk-of-bias Bar Chart for Low Risk-of-bias Animal Histopathology Studies Following Fluoride Exposure

An interactive version of Figure D-38 and additional study details in HAWC here (https://hawcproject.org/summary/visual/592/) (NTP 2019).

Figure D-39

Risk-of-bias Heatmap for High Risk-of-bias Animal Histopathology Studies Following Fluoride Exposure

An interactive version of Figure D-39 and additional study details in HAWC here (https://hawcproject.org/summary/visual/593/) (NTP 2019).

Figure D-40

Risk-of-bias Bar Chart for High Risk-of-bias Animal Histopathology Studies Following Fluoride Exposure

An interactive version of Figure D-40 and additional study details in HAWC here (https://hawcproject.org/summary/visual/594/) (NTP 2019).