# Appendix A Data Figures: Neurodevelopmental or Cognitive Effects and Outcomes

Figure A-1

Distribution of IQ in Children by Fluoride Exposure (Low Risk-of-bias Studies; Presented as % in Area or % of Total Group)

Reference group indicated by blue bars; other bars represent response estimates with red indicating statistical significance compared with the reference group.

An interactive version of Figure A-1 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/FigA1-IQ-low-rob_percent/) (NTP 2019). “F” represents fluoride. For IQ distribution results by drinking water fluoride level provided in Xiang et al. (2003a), Trivedi et al. (2012), Sudhir et al. (2009), and Seraj et al. (2012), and rate of low IQ scores by fluoride intake provided in Wang et al. (2012), statistical significance was not evaluated.

Figure A-2

Mean IQ in Children by Fluoride Exposure (Low Risk-of-bias Studies)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-2 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/Figure-A2-Mean-IQ-low-rob/) (NTP 2019) “F” represents fluoride. Three additional publications based on subsample of the larger Yu et al. (2018) cohort were identified (Zhao et al. 2019; Zhao et al. 2020; Zhou et al. 2019); however, results from these studies are not presented here. The main study by Yu et al. (2018) is considered a better representation of the IQ results. For all studies, SDs are available and can be viewed in HAWC (NTP 2019) by clicking the data points within the plot area; however, 95% CIs could not be calculated for Seraj et al. (2012) because Ns are not available for exposure groups.

Figure A-3

Intelligence Grade in Children by Fluoride Exposure (Low Risk-of-bias Studies; Presented as Mean)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-3 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/FigA3_intelligence-grade-children-low-rob/) (NTP 2019). For Saxena et al. (2012), children’s intelligence was measured using Raven’s Standard Progressive Matrices. Children’s scores were converted to percentile, and specific grades were allotted based on the percentiles. Grades ranged from intellectually superior (Grade I) to intellectually impaired (Grade V). Results for Soto-Barreras et al. (2019) are not presented here. Outcomes in the study were presented as levels of fluoride exposure associated with each intelligence grade. Results reported were not significant.

Figure A-4

Mean Change in IQ in Children by Fluoride Exposure (Low Risk-of-bias Studies)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-4 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/Figure-A4-Mean-Change-in-IQ-in-Children/) (NTP 2019). For Ding et al. (2011), SDs are available and can be viewed in HAWC (NTP 2019) by clicking the data points within the plot area; however, 95% CIs could not be calculated because Ns for each exposure group are not available.

Figure A-5

Associations between Fluoride Exposure and IQ Scores in Children (Low Risk-of-bias Studies; Presented as Adjusted OR)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance. Cutoffs for the dichotomous outcome are listed in the Endpoint column.

An interactive version of Figure A-5 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/100-test-scores-low-or-moderate-rob-studies_adjOR/) (NTP 2019). For Xiang et al. (2011), there was a significant linear trend across different levels of serum fluoride for IQ score <80 (p < 0.001). For Yu et al. (2018), significance levels by IQ score were not reported.

Figure A-6

Correlations between Fluoride Exposure and IQ Score in Children (Low Risk-of-bias Studies; Presented as Correlation Coefficient)

Circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-6 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/100-test-scores-low-or-moderate-rob-studies_coeff/) (NTP 2019). “F” represents fluoride. For Saxena et al. (2012), a significant relationship between water fluoride level and intelligence grade was observed. Increasing intelligence grades reflected increasing levels of impairment (reduced intelligence) in children.

Figure A-7

Associations between Fluoride Exposure and IQ Score in Children (Low Risk-of-bias Studies; Presented as Adjusted Beta)—China

Circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-7 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/figure-A07-china-human-data-iq-children-lower-rob/query-update/) (NTP 2019). “F” represents fluoride. For Yu et al. (2018), authors note an obvious decrease in the IQ score at water fluoride exposure levels between 3.40 mg/L and 3.90 mg/L and a similar adverse effect on IQ scores at urinary fluoride exposure levels from 1.60 mg/L to 2.50 mg/L, and so the changes in IQ score are indicated as significant; however, significance levels for change in IQ score were not reported.

Figure A-8

Associations between Fluoride Exposure and IQ Score in Children (Low Risk-of-bias Studies; Presented as Adjusted Beta)—Areas Other Than China

Circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-8 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/figure-A8-other-china-human-data-iq-children-lowe/) (NTP 2019). “F” represents fluoride.

Figure A-9

Mean Motor/Sensory Scores in Children by Fluoride Exposure (Low Risk-of-bias Studies)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-9 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/0_human_figA9_mean-scores-children-fluoride-exposu/) (NTP 2019). “F” represents fluoride. 95% CIs are small and are within figure symbols and may be difficult to see. Values for SDs and 95% CIs can be viewed in HAWC (NTP 2019) by clicking the data points within the plot area. Total neonatal behavioral neurological assessment (NBNA) score was also significantly reduced in the endemic F region versus reference region (not shown).

Figure A-10

Correlations between Fluoride Exposure and Other Cognitive Effects in Children (Low Risk-of-bias Studies; Presented as Correlation Coefficient)

Circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-10 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/0_human_figA10_correlations-between-other-neuro/) (NTP 2019). “F” represents fluoride.

Figure A-11

Associations between Fluoride Exposure and Other Neurodevelopmental Effects in Children (Low Risk-of-bias Studies; Presented as Adjusted Beta)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-11 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/100-test-scores-low-or-moderate-rob-studies_adjB/) (NTP 2019). “F” represents fluoride. Bashash et al. (2018) observed significant associations between maternal urinary fluoride and ADHD-like symptoms related to inattention (an increase in 0.5 mg/L of maternal urinary fluoride was associated with a 2.84-point increase in the DSM-IV Inattention Index and a 2.54-point increase in Cognitive Problems and Inattention Index). These two scales contributed to the global ADHD Index and the DSM-IV ADHD Total Index shown here.

Figure A-12

Associations between Fluoride Exposure and Other Neurodevelopmental Effects in Children (Low Risk-of-bias Studies; Presented as Adjusted OR)

Circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-12 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/figure-A12-human-data-other-neurological-effects-c/) (NTP 2019). “F” represents fluoride. Drinking water results for Barberio et al. (2017b) have a large confidence interval and are not completely visible in the figure. 95% CIs are 0.068–11.33 and can be viewed in HAWC (NTP 2019) by clicking the OR within the plot area.

Figure A-13

Cognitive Impairment in Adults by Fluoride Exposure (Low Risk-of-bias Studies; Presented as % of Total Group)

Reference group indicated by blue triangles; circles represent response estimates with red indicating statistical significance.

An interactive version of Figure A-13 and additional study details in HAWC here (https://hawcproject.org/summary/data-pivot/assessment/405/0_human_figA13_cognitive-impairment-adults-fluorid/) (NTP 2019). Results from Li et al. (2016) suggested that fluoride exposure may be a risk factor for cognitive impairment in elderly subjects; however, results from the study were not conducive to presentation in this visualization.