# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-5144

DOI: https://doi.org/10.22427/NTP-MGRAPH-7

Report Series: NTP Monograph Series

Report Series Number: 07

Official citation: National Toxicology Program (NTP). 2019. NTP monograph on the systematic review of traffic-related air pollution and hypertensive disorders of pregnancy. Research Triangle Park, NC: National Toxicology Program. NTP Monograph 07.