# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Monograph on the Systematic Review of Traffic-related Air Pollution and Hypertensive Disorders of Pregnancy by letter in August 2019 by the experts listed below. NTP announced the availability of the draft document in the Federal Register (84 FR 29529, June 24, 2019), and opportunities were provided for submission of written public comments. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Comment on whether the draft NTP Monograph on Traffic-Related Air Pollution and Hypertensive Disorders of Pregnancy is technically correct, clearly stated, and objectively presented.
2. Determine whether the scientific evidence from human and animal studies supports the NTP’s confidence ratings in the bodies of evidence regarding hypertensive disorders of pregnancy following exposure to individual TRAP components.
3. Determine whether the scientific evidence from human and animal studies supports the NTP’s level of evidence conclusions regarding hypertensive disorders of pregnancy following TRAP exposure in the combined body of evidence.
4. Determine whether the scientific evidence supports NTP’s policy decisions for hazard categorization on hypertensive disorders of pregnancy following TRAP exposure.

NTP carefully considered reviewer comments in finalizing this monograph.

## Peer Reviewers

- Rebecca Schmidt, Ph.D.
  Assistant Professor, Department of Public Health Sciences
  University of California, Davis, School of Medicine
  Davis, California, USA
- Karen Racicot, Ph.D.
  Assistant Professor, Department of Obstetrics, Gynecology, and Reproductive Biology
  Michigan State University, College of Human Medicine
  East Lansing, Michigan, USA
- Amy Padula, Ph.D.
  Assistant Professor, Department of Obstetrics, Gynecology, and Reproductive Sciences
  University of California, San Francisco
  San Francisco, California, USA
- Matthew Campen, Ph.D.
  Regents’ Professor, Department of Pharmaceutical Sciences
  University of New Mexico, College of Pharmacy
  Albuquerque, New Mexico, USA
- Alex Carll, Ph.D.
  Assistant Professor, Department of Physiology
  University of Louisville, School of Medicine
  Louisville, Kentucky, USA