# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Contributed to conception or design and drafting of report
  Brandiese E.J. Beverly, Ph.D., Project Lead
  Andrew A. Rooney, Ph.D.
- Assessed risk of bias, contributed to meta-analysis, and critically reviewed draft report
  Kyla W. Taylor, Ph.D.
- Screened studies, extracted data, and contributed to conception, design, and drafting of protocol
  Kembra L. Howdeshell, Ph.D.
- ICF, Fairfax, Virginia, USA
  Assessed risk of bias, screened studies, and extracted data
  Robyn B. Blain, Ph.D.
  Alexandra E. Goldstone, M.P.H., Lead Work Assignment Manager
- Conducted meta-analysis
  Sorina E. Eftim, Ph.D.
  Alexandra E. Goldstone, M.P.H., Lead Work Assignment Manager