# References

Abraham E, Rousseaux S, Agier L, Giorgis-Allemand L, Tost J, Galineau J, Hulin A, Siroux V, Vaiman D, Charles MA, et al. 2018. Pregnancy exposure to atmospheric pollution and meteorological conditions and placental DNA methylation. Environ Int. 118:334–347. 10.1016/j.envint.2018.05.007 29935799
Agency for Healthcare Research Quality (AHRQ).2014. AHRQ training modules for the systematic reviews methods guide. https://www.effectivehealthcare.ahrq.gov/index.cfm/tools-and-resources/slide-library/.
Assibey-Mensah V, Glantz JC, Hopke PK, Jusko TA, Thevenet-Morrison K, Chalupa D, Rich DQ. 2019. Ambient wintertime particulate air pollution and hypertensive disorders of pregnancy in Monroe County, New York. Environ Res. 168:25–31. 10.1016/j.envres.2018.09.003 30253313
Bauer ST, Cleary KL.2009. Cardiopulmonary complications of pre-eclampsia. Seminars in Perinatoloy. 33(3):158-165. 10.1053/j.semperi.2009.02.008
Bellamy L, Casas JP, Hingorani AD, Williams DJ. 2007. Pre-eclampsia and risk of cardiovascular disease and cancer in later life: Systematic review and meta-analysis. Br Med J (Clin Res Ed). 335(7627):974. 10.1136/bmj.39335.385301.BE 17975258
Boeldt DS, Bird IM. 2017. Vascular adaptation in pregnancy and endothelial dysfunction in preeclampsia. J Endocrinol. 232(1):R27–R44. 10.1530/JOE-16-0340 27729465
Boothe VL, Boehmer TK, Wendel AM, Yip FY. 2014. Residential traffic exposure and childhood leukemia: A systematic review and meta-analysis. Am J Prev Med. 46(4):413–422. 10.1016/j.amepre.2013.11.004 24650845
Brook RD, Rajagopalan S. 2009. Particulate matter, air pollution, and blood pressure. J Am Soc Hypertens. 3(5):332–350. 10.1016/j.jash.2009.08.005 20409976
Choe SA, Kauderer S, Eliot MN, Glazer KB, Kingsley SL, Carlson L, Awad YA, Schwartz JD, Savitz DA, Wellenius GA. 2018. Air pollution, land use, and complications of pregnancy. Sci Total Environ. 645:1057–1064. 10.1016/j.scitotenv.2018.07.237 30248831
Clark SL, Cotton DB, Lee W, Bishop C, Hill T, Southwick J, Pivarnik J, Spillman T, DeVore GR, Phelan J. 1989. Central hemodynamic assessment of normal term pregnancy. Am J Obstet Gynecol. 161(6):1439–1442. 10.1016/0002-9378(89)90900-9 2603895
Cochran WG. 1954. The combination of estimates from different experiments. Biometrics. 10(1):101–129.10.2307/3001666
Conde-Agudelo A, Althabe F, Belizan JM, Kafury-Goeta AC. 1999. Cigarette smoking during pregnancy and risk of preeclampsia: A systematic review. Am J Obstet Gynecol. 181(4):1026–1035. 10.1016/S0002-9378(99)70341-8 10521771
Coogan PF, White LF, Jerrett M, Brook RD, Su JG, Seto E, Burnett R, Palmer JR, Rosenberg L. 2012. Air pollution and incidence of hypertension and diabetes mellitus in black women living in Los Angeles. Circulation. 125(6):767–772. 10.1161/CIRCULATIONAHA.111.052753 22219348
Costa J, Rice H, Cardwell C, Hunter A, Ong S. 2010. An assessment of vascularity and flow intensity of the placenta in normal pregnancy and pre-eclampsia using three-dimensional ultrasound. J Matern Fetal Neonatal Med. 23(8):894–899. 10.3109/14767051003649862 20230318
Dadvand P, Figueras F, Basagana X, Beelen R, Martinez D, Cirach M, Schembari A, Hoek G, Brunekreef B, Nieuwenhuijsen MJ. 2013. Ambient air pollution and preeclampsia: A spatiotemporal analysis. Environ Health Perspect. 121(11-12):1365–1371. 10.1289/ehp.1206430 24021707
DerSimonian R, Laird N. 1986. Meta-analysis in clinical trials. Control Clin Trials. 7(3):177–188. 10.1016/0197-2456(86)90046-2 3802833
Doyle LW. 2008. Cardiopulmonary outcomes of extreme prematurity. Semin Perinatol. 32(1):28–34. 10.1053/j.semperi.2007.12.005 18249237
Duley L. 2009. The global impact of pre-eclampsia and eclampsia. Semin Perinatol. 33(3):130–137. 10.1053/j.semperi.2009.02.010 19464502
Egger M, Smith GD, Schneider M, Minder C. 1997. Bias in meta-analysis detected by a simple, graphical test. Br Med J (Clin Res Ed). 315(7109):629–634. 10.1136/bmj.315.7109.629 9310563
Engel SM, Scher E, Wallenstein S, Savitz DA, Alsaker ER, Trogstad L, Magnus P. 2013. Maternal active and passive smoking and hypertensive disorders of pregnancy: Risk with trimester-specific exposures. Epidemiology. 24(3):379–386. 10.1097/EDE.0b013e3182873a73 23429405
England L, Zhang J. 2007. Smoking and risk of preeclampsia: A systematic review. Front Biosci. 12:2471–2481. 10.2741/2248 17127256
Fecht D, Hansell AL, Morley D, Dajnak D, Vienneau D, Beevers S, Toledano MB, Kelly FJ, Anderson HR, Gulliver J. 2016. Spatial and temporal associations of road traffic noise and air pollution in London: Implications for epidemiological studies. Environ Int. 88:235–242. 10.1016/j.envint.2015.12.001 26773394
Gamboa A, Shibao C, Diedrich A, Choi L, Pohar B, Jordan J, Paranjape S, Farley G, Biaggioni I. 2007. Contribution of endothelial nitric oxide to blood pressure in humans. Hypertension. 49(1):170–177. 10.1161/01.HYP.0000252425.06216.26 17130304
George EM, Granger JP. 2011. Mechanisms and potential therapies for preeclampsia. Curr Hypertens Rep. 13(4):269–275. 10.1007/s11906-011-0204-0 21465139
Guo Y, Barnett AG, Zhang Y, Tong S, Yu W, Pan X. 2010. The short-term effect of air pollution on cardiovascular mortality in Tianjin, China: Comparison of time series and case–crossover analyses. Sci Total Environ. 409(2):300–306. 10.1016/j.scitotenv.2010.10.013 21055792
Guyatt GH, Oxman AD, Akl EA, Kunz R, Vist G, Brozek J, Norris S, Falck-Ytter Y, Glasziou P, Debeer H, et al. 2011. GRADE guidelines: 1. Introduction-GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. 64(4):383–394. 10.1016/j.jclinepi.2010.04.026 21195583
Haberzettl P, Conklin DJ, Abplanalp WT, Bhatnagar A, O’Toole TE. 2018. Inhalation of fine particulate matter impairs endothelial progenitor cell function via pulmonary oxidative stress. Arterioscler Thromb Vasc Biol. 38(1):131–142. 10.1161/ATVBAHA.117.309971 29191925
Health Effects Institute (HEI).2010. Traffic-related air pollution: A critical review of the literature on emissions, exposure, and health effects. Boston, MA: Health Effects Institute.https://www.healtheffects.org/publication/traffic-related-air-pollution-critical-review-literature-emissions-exposure-and-health.
Hettfleisch K, Bernardes LS, Carvalho MA, Pastro LD, Vieira SE, Saldiva SR, Saldiva P, Francisco RP. 2017. Short-term exposure to urban air pollution and influences on placental vascularization indexes. Environ Health Perspect. 125(4):753–759. 10.1289/EHP300 27384326
Higgins JPT, Green S. 2011. Cochrane Handbook for Systematic Reviews of Interventions. The Cochrane Collaboration.
Hu H, Ha S, Roth J, Kearney G, Talbott EO, Xu X. 2014. Ambient air pollution and hypertensive disorders of pregnancy: A systematic review and meta-analysis. Atmos Environ. 97:336–345. 10.1016/j.atmosenv.2014.08.027 25242883
Jeyabalan A, Powers RW, Durica AR, Harger GF, Roberts JM, Ness RB. 2008. Cigarette smoke exposure and angiogenic factors in pregnancy and preeclampsia. Am J Hypertens. 21(8):943–947. 10.1038/ajh.2008.219 18566591
Karumanchi SA, Levine RJ. 2010. How does smoking reduce the risk of preeclampsia? Hypertension. 55(5):1100–1101. 10.1161/HYPERTENSIONAHA.109.148973 20231524
Krupp J, Boeldt DS, Yi FX, Grummer MA, Bankowski Anaya HA, Shah DM, Bird IM. 2013. The loss of sustained Ca(2+) signaling underlies suppressed endothelial nitric oxide production in preeclamptic pregnancies: Implications for new therapy. Am J Physiol. 305(7):H969–H979. 10.1152/ajpheart.00250.2013 23893163
Krzyzanowski M, Vandenberg J, Stieb D. 2005. Perspectives on air quality policy issues in Europe and North America. J Toxicol Environ Health. 68(13-14):1057–1061. 10.1080/15287390590935897 16024487
Lassegue B, Griendling KK. 2004. Reactive oxygen species in hypertension: An update. Am J Hypertens. 17(9):852–860. 10.1016/j.amjhyper.2004.02.004 15363831
Link MS, Dockery DW. 2010. Air pollution and the triggering of cardiac arrhythmias. Curr Opin Cardiol. 25(1):16–22. 10.1097/HCO.0b013e32833358cd 19881339
Madsen C, Haberg SE, Aamodt G, Stigum H, Magnus P, London SJ, Nystad W, Nafstad P. 2018. Preeclampsia and hypertension during pregnancy in areas with relatively low levels of traffic air pollution. Matern Child Health J. 22(4):512–519. 10.1007/s10995-017-2417-6 29285630
Malmqvist E, Jakobsson K, Tinnerberg H, Rignell-Hydbom A, Rylander L. 2013. Gestational diabetes and preeclampsia in association with air pollution at levels below current air quality guidelines. Environ Health Perspect. 121(4):488–493. 10.1289/ehp.1205736 23563048
Mantel N, Haenszel W. 1959. Statistical aspects of the analysis of data from retrospective studies of disease. J Natl Cancer Inst. 22(4):719–748. 13655060
Miller CN, Stewart EJ, Snow SJ, Williams WC, Richards JH, Thompson LC, Schladweiler MC, Farraj AK, Kodavanti UP, Dye JA. 2019. Ozone exposure during implantation increases serum bioactivity in HTR-8/SVneo trophoblasts. Toxicol Sci. 168(2):535–550. 10.1093/toxsci/kfz003 30649513
Miranda ML, Edwards SE, Chang HH, Auten RL. 2013. Proximity to roadways and pregnancy outcomes. J Expo Sci Environ Epidemiol. 23(1):32–38. 10.1038/jes.2012.78 22805991
Mozaffarian D, Benjamin EJ, Go AS, Arnett DK, Blaha MJ, Cushman M, Das SR, de Ferranti S, Despres JP, Fullerton HJ, et al. 2016. Heart disease and stroke statistics-2016 update: A report from the American Heart Association. Circulation. 133(4):e38–e360. 10.1161/CIR.0000000000000350 26673558
National Toxicology Program (NTP).2015. Handbook for conducting a literature-based health assessment using OHAT approach for systematic review and evidence integration - January 9 2015. RTP, NC.https://ntp.niehs.nih.gov/go/38673. [Accessed: 25 Jan 2015]
National Toxicology Program (NTP).2019a. Health Assessment Workspace Collaborative (HAWC) page for traffic-related air pollution and hypertensive disorders during pregnancy.https://hawcproject.org/assessment/60/.
National Toxicology Program (NTP).2019b. MGRAPH-7: Traffic-related air pollution and hypertensive disorders of pregnancy supplementary files. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program.10.22427/NTP-DATA-MGRAPH-7.
Nedeljkovic ZS, Gokce N, Loscalzo J. 2003. Mechanisms of oxidative stress and vascular dysfunction. Postgrad Med J. 79(930):195–199, quiz 198–200. 10.1136/pmj.79.930.195 12743334
Olsson D, Mogren I, Eneroth K, Forsberg B.2015. Traffic pollution at the home address and pregnancy outcomes in Stockholm, Sweden. Br Med J Open. 5(8):e007034. 10.1136/bmjopen-2014-007034
Pedersen M, Halldorsson TI, Olsen SF, Hjortebjerg D, Ketzel M, Grandstrom C, Raaschou-Nielsen O, Sorensen M. 2017. Impact of road traffic pollution on pre-eclampsia and pregnancy-induced hypertensive disorders. Epidemiology. 28(1):99–106. 10.1097/EDE.0000000000000555 27648591
Pedersen M, Stayner L, Slama R, Sorensen M, Figueras F, Nieuwenhuijsen MJ, Raaschou-Nielsen O, Dadvand P. 2014. Ambient air pollution and pregnancy-induced hypertensive disorders: A systematic review and meta-analysis. Hypertension. 64(3):494. -+. . 10.1161/HYPERTENSIONAHA.114.03545 24935943
Pereira G, Haggar F, Shand AW, Bower C, Cook A, Nassar N. 2013. Association between pre-eclampsia and locally derived traffic-related air pollution: A retrospective cohort study. J Epidemiol Community Health. 67(2):147–152. 10.1136/jech-2011-200805 22879639
Rooney AA, Boyles AL, Wolfe MS, Bucher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Rooney AA, Cooper GS, Jahnke GD, Lam J, Morgan RL, Boyles AL, Ratcliffe JM, Kraft AD, Schünemann HJ, Schwingl P, et al. 2016. How credible are the study results? Evaluating and applying internal validity tools to literature-based assessments of environmental health hazards. Environ Int. 92-93:617–629. 10.1016/j.envint.2016.01.005 26857180
Rudra CB, Williams MA, Sheppard L, Koenig JQ, Schiff MA. 2011. Ambient carbon monoxide and fine particulate matter in relation to preeclampsia and preterm delivery in western Washington State. Environ Health Perspect. 119(6):886–892. 10.1289/ehp.1002947 21262595
Savitz DA, Elston B, Bobb JF, Clougherty JE, Dominici F, Ito K, Johnson S, McAlexander T, Ross Z, Shmool JL, et al. 2015. Ambient fine particulate matter, nitrogen dioxide, and hypertensive disorders of pregnancy in New York City. Epidemiology. 26(5):748–757. 10.1097/EDE.0000000000000349 26237745
Sears CG, Braun JM, Ryan PH, Xu Y, Werner EF, Lanphear BP, Wellenius GA. 2018. The association of traffic-related air and noise pollution with maternal blood pressure and hypertensive disorders of pregnancy in the HOME study cohort. Environ Int. 121(Pt 1):574–581. 10.1016/j.envint.2018.09.049 30300815
Sorensen M, Hoffmann B, Hvidberg M, Ketzel M, Jensen SS, Andersen ZJ, Tjonneland A, Overvad K, Raaschou-Nielsen O. 2012. Long-term exposure to traffic-related air pollution associated with blood pressure and self-reported hypertension in a Danish cohort. Environ Health Perspect. 120(3):418–424. 10.1289/ehp.1103631 22214647
StataCorp. 2017. Stata statistical software: Release 15. College Station, TX: StataCorp LLC.
Sun Q, Yue P, Ying Z, Cardounel AJ, Brook RD, Devlin R, Hwang JS, Zweier JL, Chen LC, Rajagopalan S. 2008. Air pollution exposure potentiates hypertension through reactive oxygen species-mediated activation of Rho/ROCK. Arterioscler Thromb Vasc Biol. 28(10):1760–1766. 10.1161/ATVBAHA.108.166967 18599801
The American College of Obstetricians Gynecologists (ACOG).2013. Hypertension in pregnancy. Washington, DC: The American College of Obstetricians and Gynecologists.https://www.acog.org/Clinical-Guidance-and-Publications/Task-Force-and-Work-Group-Reports/Hypertension-in-Pregnancy.
U.S. Environmental Protection Agency (USEPA).2008. Integrated Science Assessment (ISA) for oxides of nitrogen and sulfur: Ecological criteria. RTP, NC: U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment. EPA/600/R-08/082F.https://cfpub.epa.gov/ncea/isa/recordisplay.cfm?deid=201485.
U.S. Environmental Protection Agency (USEPA).2009. Integrated Science Assessment (ISA) for particulate matter. RTP, NC: U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment. EPA/600/R-08/139F.https://cfpub.epa.gov/ncea/risk/recordisplay.cfm?deid=216546.
U.S. Environmental Protection Agency (USEPA).2010. Integrated Science Assessment (ISA) for carbon monoxide. RTP, NC: U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment. EPA/600/R-09/019F.https://cfpub.epa.gov/ncea/isa/recordisplay.cfm?deid=218686.
U.S. Environmental Protection Agency (USEPA).2016. Integrated Science Assessment (ISA) for oxides of nitrogen-health criteria (final report). RTP, NC: U.S. Environmental Protection Agency, Office of Research and Development, National Center for Environmental Assessment. EPA/600/R-15/068.https://cfpub.epa.gov/ncea/isa/recordisplay.cfm?deid=310879.
van den Hooven EH, de Kluizenaar Y, Pierik FH, Hofman A, van Ratingen SW, Zandveld PY, Mackenbach JP, Steegers EA, Miedema HM, Jaddoe VW. 2011. Air pollution, blood pressure, and the risk of hypertensive complications during pregnancy: The generation R study. Hypertension. 57(3):406–412. 10.1161/HYPERTENSIONAHA.110.164087 21220700
van den Hooven EH, Jaddoe VW, de Kluizenaar Y, Hofman A, Mackenbach JP, Steegers EA, Miedema HM, Pierik FH. 2009. Residential traffic exposure and pregnancy-related outcomes: A prospective birth cohort study. Environ Health. 8:59. 10.1186/1476-069X-8-59 20028508
Venditti CC, Casselman R, Young I, Karumanchi SA, Smith GN. 2014. Carbon monoxide prevents hypertension and proteinuria in an adenovirus sFlt-1 preeclampsia-like mouse model. PLoS One. 9(9). 10.1371/journal.pone.0106502 25202912
Wang Y, Gu Y, Loyd S, Jia X, Groome LJ. 2015. Increased urinary levels of podocyte glycoproteins, matrix metallopeptidases, inflammatory cytokines, and kidney injury biomarkers in women with preeclampsia. Am J Physiol. 309(12):F1009–F1017. 10.1152/ajprenal.00257.2015 26671966
Wei J, Liu CX, Gong TT, Wu QJ, Wu L. 2015. Cigarette smoking during pregnancy and preeclampsia risk: A systematic review and meta-analysis of prospective studies. Oncotarget. 6(41):43667–43678. 10.18632/oncotarget.6190 26498356
Wikstrom AK, Stephansson O, Cnattingius S. 2010. Tobacco use during pregnancy and preeclampsa risk: Effects of cigarette smoking and snuff. Hypertension. 55(5):1254–1259. 10.1161/HYPERTENSIONAHA.109.147082 20231527
World Health Organization (WHO).2016. Ambient (outdoor) air quality and health: Fact sheet. World Health Organization.https://www.who.int/mediacentre/factsheets/fs313/en/.
Wu J, Wilhelm M, Chung J, Ritz B. 2011. Comparing exposure assessment methods for traffic-related air pollution in an adverse pregnancy outcome study. Environ Res. 111(5):685–692. 10.1016/j.envres.2011.03.008 21453913
Wu M, Ries JJ, Proietti E, Vogt D, Hahn S, Hoesli I. 2016. Development of late-onset preeclampsia in association with road densities as a proxy for traffic-related air pollution. Fetal Diagn Ther. 39(1):21–27. 10.1159/000381802 26088708
Yorifuji T, Naruse H, Kashima S, Murakoshi T, Doi H. 2015. Residential proximity to major roads and obstetrical complications. Sci Total Environ. 508:188–192. 10.1016/j.scitotenv.2014.11.077 25478655