# Conclusion

NTP concludes that exposure to traffic-related air pollution (TRAP) is presumed to be a hazard to pregnant women for developing hypertensive disorders of pregnancy based on the available evidence across multiple measures of TRAP exposure (i.e., traffic-related PM_2.5_ and NO_2_) with support from studies on traffic measures (residing in high-traffic density regions or in close proximity to major roads during pregnancy).

The effect of TRAP was consistent across bodies of evidence for individual TRAP components and was supported by meta-analyses for individual traffic-related air pollutants (i.e., PM_2.5_ and NO_2_). There is a similar pattern of findings, but smaller effect sizes, for bodies of evidence that residing in high-traffic density regions or in close proximity to major roads are associated with developing hypertensive disorders during pregnancy. The collective evidence across the air pollutant measures and the traffic measures shows consistency in the direction of effect across multiple populations and geographic locations, strengthening the confidence in the association between the combined TRAP exposure (versus exposure to the individual TRAP components) and hypertensive disorders of pregnancy. The combined body of evidence is more robust due to the greater number of studies, the multiple mechanisms by which the individual components can affect blood pressure, and the greater likelihood of exposure to multiple components of TRAP.

Overall, the available evidence supports that exposure to TRAP increases the odds for developing hypertensive disorders of pregnancy. Because of the recognized relationship between maternal blood pressure status and the effect of hypertension during pregnancy on fetal and infant health outcomes, hypertensive disorders of pregnancy associated with TRAP exposure may have significant adverse health effects in the developing offspring.