# Discussion

Following a systematic review of the evidence, the National Toxicology Program (NTP) reached conclusions on hypertensive disorders of pregnancy following exposures to traffic-related air pollution (TRAP). NTP concludes that exposure to TRAP is presumed to be a hazard to pregnant women on the basis of the available evidence across multiple measures of TRAP exposure (e.g., traffic-related fine particulate matter [PM_2.5_] and nitrogen dioxide [NO_2_], residing in high-traffic density regions or in close proximity to major roads) and that TRAP is associated with the development of hypertensive disorders of pregnancy. The overall hazard conclusion was based on moderate confidence and moderate level of evidence in the human evidence for the combined TRAP exposure.

The hazard conclusion for combined TRAP exposure was considered to better reflect true exposure to TRAP than individual measures of exposure. The effect of TRAP was consistent across bodies of evidence for individual components and was supported by meta-analyses for individual traffic-related metrics (i.e., PM_2.5_ and NO_2_). When considered together, evidence across the air pollutant and traffic measures collectively showed consistency in the direction of effect across multiple populations and geographic locations, strengthening the confidence in the association between the combined TRAP exposure and hypertensive disorders of pregnancy compared with exposure to individual TRAP components and this outcome. Many studies evaluated only one TRAP component (with or without a traffic measurement), and those that evaluated more than one component still found significant associations between the individual components and hypertensive disorders of pregnancy after statistically accounting for other exposures. The robustness of the body of evidence for the combined TRAP exposure due to the greater number of studies, the consistency in the direction of the effect across multiple populations and geographic locations, and the high likelihood of exposure to multiple TRAP components strengthened the confidence in the evidence for combined TRAP exposure compared with exposure to the individual TRAP components, resulting in a hazard conclusion of presumed to be a hazard to pregnant women.

In addition to the evidence for PM_2.5_, NO_2_, and traffic measures, a few studies were available that investigated potential associations between carbon monoxide (CO), black carbon (BC), or elemental carbon (EC) and hypertensive disorders of pregnancy. Although findings from the epidemiological studies for CO exposure were unclear, the experimental animal study used in this assessment (as well as other studies evaluating the effects of smoking on blood pressure during pregnancy) suggest carbon monoxide may promote vasodilation and reduce the risk of preeclampsia (Conde-Agudelo et al. 1999; Engel et al. 2013; England and Zhang 2007; Jeyabalan et al. 2008; Karumanchi and Levine 2010; Wei et al. 2015; Wikstrom et al. 2010). However, consistent with the observed associations between TRAP components and hypertensive disorders of pregnancy, potential protective effects of CO on blood pressure do not appear to be mitigating the associations between TRAP and hypertensive disorders of pregnancy. This is further illustrated by small but positive associations between traffic measures (which would include the totality of traffic-related air pollutants, including CO) and hypertensive disorders of pregnancy, supporting an overall effect of TRAP on this outcome. The few studies in the available evidence for BC and EC exposures are inadequate for reaching meaningful conclusions.

## Potential Mechanisms

The mechanisms by which TRAP components increase blood pressure during pregnancy is not entirely understood, and a mechanistic understanding is challenged by the complexity of the series of adaptive processes that occur for a healthy pregnancy. However, insights from mechanistic studies that demonstrate how blood pressure is elevated in the nonpregnant state show significant overlap with mechanisms that appear to play a role in the pathogenesis of preeclampsia, thus providing a plausible mechanism for the observed association between TRAP exposure and increased risk for hypertensive disorders. Exposure to PM can induce endothelial and/or smooth muscle dysfunction through vascular inflammation and oxidative stress pathways (Haberzettl et al. 2018). NO_2_ exposures can also induce oxidative stress. In addition, changes in autonomic nervous system (ANS) balance favoring sympathetic nervous system-mediated arterial vasoconstriction, the generation and release of endogenous biological mediators from various sources (most notably from lung cells), and/or potential direct vascular actions of PM constituents that can reach the systemic circulation may all contribute to hypertension. TRAP-mediated increases in blood pressure likely occur in a biphasic manner, with an initial response caused by rapid changes in ANS balance followed by increased sensitivity to vasoconstrictive responses (Link and Dockery 2010) [reviewed in Brook and Rajagopalan (2009)].

During a normal healthy pregnancy, highly coordinated events occur to ensure adequate blood flow to the placenta and fetus and to facilitate the exchange of gas and nutrients. This process includes early vascular adaptations that begin during embryo implantation in the uterus, resulting in a series of migration and invasion events by fetus-derived cytotrophoblasts into the maternal spiral arteries. These invasive trophoblasts gradually replace the endothelial lining of the spiral arteries, themselves undergoing a shift to become endothelial-like cells, to remodel these normally low capacitance, high resistance vessels to high capacitance, low resistance vessels by the second trimester (reviewed in George and Granger (2011)). In addition, maternal hormones increase blood volume, and cardiac output increases by up to 50% compared with the nonpregnant state, with the majority of this change occurring during the first 8 weeks of pregnancy (Clark et al. 1989). Such a change in the nonpregnant state would result in a compensatory increase in vascular resistance and blood pressure to maintain homeostasis. However, during pregnancy, the increase in blood volume and cardiac output is associated with a decrease in blood pressure because of the general decrease in vascular resistance resulting from the early arterial remodeling events. Although vascular resistance decreases throughout the body, there is a disproportionally large drop in vascular resistance in the uterine circulation, resulting in a greater proportion of the cardiac output going to the uteroplacental unit to meet the demands of the growing fetus (reviewed in Boeldt and Bird (2017)).

Although the data are limited, some studies have suggested associations between diminished vascularization indices in the placenta during the first trimester of pregnancy and air pollutants, particularly NO_2_ (Hettfleisch et al. 2017). These indices have been shown to be lower in patients with preeclampsia compared with normotensive pregnancies (Costa et al. 2010). Animal studies evaluating ozone exposure during pregnancy have also demonstrated impaired implantation processes and impaired trophoblast metabolic capacity (Miller et al. 2019), and as technologies continue to improve, these relationships will be explored in more detail and may provide more insight on the role of air pollutants on blood flow to the placenta and subsequent effects.

In addition, a large body of literature has highlighted the importance of endothelial cells in the normal adaptive processes of pregnancy, and endothelial dysfunction is a key event that contributes to all major symptoms of preeclampsia. Endothelial cells play a critical role on the control of vascular function by sensing the blood composition as well as providing a physical barrier to the improper movement of water, ions, proteins, and cells from the blood vessel into the vessel walls. In women who develop hypertensive disorders of pregnancy, there is evidence to suggest that these key physiologic functions of endothelial cells are compromised (Boeldt and Bird 2017). Long-term exposure to constituents of PM can induce an inflammatory response and oxidative stress, which has been shown to play a causal role in the endothelial cell dysfunction and impaired vasomotor balance observed in humans and animal models in the nonpregnant state (Gamboa et al. 2007; Lassegue and Griendling 2004; Nedeljkovic et al. 2003; Sun et al. 2008). Activation of inflammation and oxidative stress pathways sensitize the vasculature to the pro-vasoconstrictive effects of endogenous mediators that lead to vasoconstriction and, ultimately, elevated blood pressure. Similar to the increased sensitivity to vasoconstrictors in the nonpregnant state, endothelial dysfunction in preeclamptic pregnancies results in a failure to develop insensitivity to vasoconstrictors as well as insufficient calcium signaling and vasodilator production (Krupp et al. 2013), causing an increase in vascular resistance. Thus, the normal increase in blood volume paired with the insufficient drop in uterine and vascular resistance contributes significantly to the hypertensive component of preeclampsia. Further, endothelial dysfunction in glomerular cells in the kidney leads to proteinuria due to the loss of barrier function integrity causing pathologically permissive protein movement into the urine (Wang et al. 2015). Direct evidence demonstrating that exposure to TRAP components during pregnancy activates inflammation and oxidative stress pathways, thus causing endothelial dysfunction and impaired sensitivity to vasoconstrictive and vasodilatory factors to increase vascular resistance and elevate blood pressure is not yet available. However, studies evaluating components of these pathways and evidence from studies in the nonpregnant state provide a biologically plausible mechanism for the observed association between TRAP exposure and hypertensive disorders of pregnancy reported in this assessment. Additional studies will be needed to test components of the proposed mode of action to support the epidemiological findings.

## Limitations of the Evidence Base

Several limitations in the body of evidence apply across the different exposures. The air pollutants identified for inclusion have been commonly used as exposure surrogates for TRAP in other evaluations. While the specificity of the exposure characterization in the inclusion criteria along with the supporting evidence from the traffic measures do increase the confidence that the exposures reported and subsequent associations with hypertensive disorders of pregnancy are due to traffic, it is recognized that many of the exposure surrogates used to identify TRAP are also generated by other sources. Thus, this limits the ability to attribute associations exclusively to traffic-derived sources. It is also likely that exposure to other TRAP components (e.g., ultrafine particles, sulfur oxides, volatile organic compounds) may contribute to the development or exacerbation of hypertensive disorders of pregnancy; however, to date, no studies have evaluated those associations. In addition, traffic noise is likely a co-exposure for all TRAP studies, but relatively few studies have tried to disentangle the possible effects of traffic noise verses TRAP. Because the correlation between the two exposures is not always colinear (Fecht et al. 2016), the extent to which TRAP is confounded by traffic noise is unclear. In addition, exposure levels are based on 2-dimensional maps and assumes pregnant women residing in tall buildings are exposed to the same levels of TRAP as those residing at ground level. Exposures are likely to be lower for women at higher levels, and this source of heterogeneity may bias the results toward the null, particularly when tall multi-unit residence buildings are colinear with traffic density and modeled exposure levels.

In general, relatively few studies evaluated TRAP and hypertensive disorders of pregnancy and almost all of the studies were cohort studies. The overall prevalence of hypertensive disorders of pregnancy in these cohorts is low, and the cases identified in these studies are likely more serious because the more severe cases are more likely to be diagnosed. Opportunities for more prospective studies and studies using larger data sets with improved data sources (e.g., electronic health records that include prenatal care) will increase the likelihood of capturing the full range of hypertensive disorders during pregnancy, including early- and late-onset preeclampsia, which are thought to have different etiologies. Although many studies stated that women with preexisting hypertension were excluded, given the challenges of accurately excluding those women (which would depend on when they began treatment and the quality of the source of the outcome assessment), considerable heterogeneity is likely within the study populations for this condition. However, women with preexisting hypertension may represent a particularly vulnerable group that warrants more evaluation because they are often understudied and at a high risk for developing pregnancy complications and other adverse outcomes, including those in their infants. In addition, no studies to date use personal sampling data or biomonitoring methods to determine exposure to TRAP in humans and use of those methods could improve the exposure data. Additional studies that better characterize actual TRAP exposures in pregnant women and evaluate outcomes of interest would increase the confidence in the body of evidence.

Finally, very few studies evaluated TRAP exposure and blood pressure parameters during pregnancy in experimental animal models. Studies conducted in nonpregnant animals can likely elucidate potential overlapping mechanisms but would not provide insight on how environmental exposures affect mechanisms related to blood pressure and hemodynamic regulation during pregnancy. Animal studies and mechanistic studies in humans or human cell-based systems could help elucidate mechanisms to strengthen overall conclusions.

## Limitations of the Systematic Review

The hazard identification conclusions in this evaluation were based solely on the epidemiological data because there were no experimental animal studies that met the specific PECO inclusion criteria, nor were there studies that evaluated hypertensive disorders of pregnancy associated with exposure to other traffic-related air pollutants (e.g., diesel, sulfur oxides, BC). Although there are studies that evaluate effects of other traffic-related air pollutants, there were no other studies that evaluated these pollutants in relation to hypertensive disorders of pregnancy that also characterized the exposure to the extent that would allow for exposure to be reasonably attributed to traffic. Additional prospective epidemiological studies with well-characterized exposure and outcome assessments would strengthen the human evidence. In addition, this evaluation focused on primary emissions from traffic sources. Although there are studies that have evaluated effects of secondary products on hypertensive disorders of pregnancy, such as ozone, inclusion of those studies was beyond the scope of this review and were not evaluated. The dearth of animal data and exposure data are significant data gaps that need to be addressed to strengthen overall conclusions about the potential causal relationship between TRAP constituents and hypertensive disorders of pregnancy.